# Conclusions

Under the conditions of this modified one-generation (MOG) study, there was no evidence of reproductive toxicity of 2-ethylhexyl p-methoxycinnamate (EHMC) in Hsd:Sprague Dawley^®^ SD^®^ rats at exposure concentrations of 1,000, 3,000, or 6,000 ppm. Mating and littering were not affected significantly by EHMC exposure.

Under the conditions of this MOG study, there was equivocal evidence of developmental toxicity of EHMC in Hsd:Sprague Dawley^®^ SD^®^ rats based on the observed postnatal effects on body weight that showed some indication of recovery by study end, delays in postnatal day 28-adjusted vaginal opening and balanopreputial separation, which could have been influenced by the apparent transient effects on body weight, and time in estrus was slightly longer in EHMC-exposed females relative to that of the control group. No other signals consistent with alterations in estrogenic, androgenic, or antiandrogenic action were observed. EHMC exposure did not induce any specific fetal malformations.