# Discussion

The objective of this study was to characterize the potential for 2-ethylhexyl p-methoxycinnamate (EHMC), a common component of sunscreen and personal care products, to adversely affect any phase of rat development, maturation, or ability to successfully reproduce, and to cause subchronic toxicity in the F_1_ generation.

Mechanistic screening studies have indicated that EHMC is capable of transactivation of the estrogen receptor (ER), inducing uterotrophic responses, and attenuating progesterone receptor transactivation.^18-20^ Given these reported findings and wide human exposure, the National Toxicology Program (NTP) conducted a study to examine the possible effects of EHMC exposure on developmental and reproductive endpoints and possible subchronic toxicity in the presence of continual EHMC exposure. As disposition is similar following oral and dermal exposures, EHMC exposure via the diet was selected for this study to sustain internal exposure and to avoid variability in internal dose from topical application and subsequent intra- and inter-animal grooming behavior. To minimize the potential endocrine activity of phytoestrogens that are often present in rodent diets, a diet low in phytoestrogens was used. Exposure concentration selection was informed by a dose range-finding study that indicated that 6,000 ppm in the feed would be well-tolerated by the dams and would likely result in approximately 10% lower pup mean body weight. The exposure concentrations of 1,000 and 3,000 ppm were selected to aid in identifying potential exposure concentration-response relationships. This spacing would ideally avoid excessive exposure overlap of the respective ingested doses of mg EHMC/kg body weight/day (mg/kg/day), recognizing that the amount of feed consumed depends on pregnancy state, sex, and age.

In contrast to previously reported in vitro and short-term rat in vivo endocrine disruptor screening studies, EHMC exposure did not appear to induce any substantial effects on androgen receptor (AR)-dependent endpoints. Although F_1_ male rats exposed to 6,000 ppm displayed a slight but significant delay in attainment of balanopreputial separation (BPS) (when adjusted for body weight on postnatal day [PND] 28) and F_1_ male rats in the subchronic cohort displayed a slight but significant decrease in absolute ventral prostate gland weight, no concomitant effects were observed in anogenital distance or male areolae/nipple retention in F_1_ or F_2_ male rats. Moreover, similar decreases in ventral prostate gland weight or decreases in any AR-dependent reproductive tissue examined were not observed in either the reproductive performance cohort or the prenatal cohort in which more male animals per exposure group had been examined. Furthermore, there were no malformations in AR-dependent tissues or histopathological findings consistent with alterations in androgen action or apparent effects of EHMC exposure on F_1_ male reproductive performance in either mating cohort, indicating a normal functioning male reproductive system. Collectively, the data suggest that the significant decrease in ventral prostate gland weight observed in the subchronic cohort was spurious. The absence of reproductive effects in male Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats in the current study are inconsistent with previously reported decreased sperm counts in Wistar Han rats following gestational and lactational EHMC exposure. The different study results could reflect different sensitivities of the two rat strains or the different dosing paradigms, gavage versus dietary. Moreover, the absence of observed EHMC-mediated effects on AR- and ER-dependent processes is consistent with that of the previously reported Endocrine Disruptor Screening Program studies that demonstrated that EHMC had no apparent effects on AR and ER binding and activation.^26^

Male and female F_1_ and F_2_ offspring exposed to EHMC displayed mean body weights similar to those of the control groups on PND 0. However, as the lactational period progressed to the point when pups started to eat feed, pups in the 3,000 and 6,000 ppm groups exhibited lower mean body weights and weight gains compared to the control animals. On PND 28, pups in the 6,000 ppm groups weighed approximately 13%–15% less than the control groups; however, by PND 91, the body weights of pups exposed to 6,000 ppm were approximately 5%–7% lower than those of the control groups, demonstrating some reversibility/recovery of the effect on body weight.

F_1_ females in the 6,000 ppm group displayed a slight but significant delay of approximately 2 days of litter mean day of vaginal opening (VO) attainment, when adjusted for body weight at weaning (PND 28). Similarly, F_1_ male animals in the 6,000 ppm group displayed a comparable 2-day delay of the litter mean day of attaining BPS when adjusted for body weight on PND 28. However, both male and female rats had similar respective body weights on day of attainment, and the magnitude of body weight suppression in the 6,000 ppm group was lessening, indicating “recovery.” Intrauterine growth retardation—after ligation of the uterine artery on gestation day (GD) 17 and resulting in 16% lower body weight on PND 2 and lower postnatal body weights relative to the control group—has been shown to delay VO.^73^ Postnatal dietary restriction also has been shown to delay VO with similar body weights at time of VO.^74^ The lower PND 4 pup and postnatal mean body weights and the delay in VO observed in the current study are consistent with these findings. Similarly, intrauterine growth retardation as well as postnatal feed restriction, resulting in lower postnatal body weights, have been shown to delay BPS.^73^ It is plausible that the similar weights on day of attainment observed in the current study, like VO, have a weight or body mass requirement for attainment of BPS to occur. Nonetheless, given the small magnitude of change, comparable mean body weights on day of attainment, and absence of alterations in AR-mediated endpoints, the observed BPS response is likely secondary to effects on growth rate and not AR-mediated. Although the delay in VO is consistent with those previously reported^22^ and occurred in the presence of apparent subtle effects on estrous cyclicity (time in estrus, increase in estrous stage length, but no effects on overall length), those effects were not commensurate with biologically significant alterations in reproductive function or postnatal support of the offspring. Given these apical delays in attainment, concomitant with effects on growth, it was unclear whether these findings were directly attributable to EHMC exposure. Markov model estimates of estrous stage length indicated a slight but significant increase in estrus stage length in all EHMC-exposed groups and respective decrease in diestrus stage length. This did not display an exposure concentration-response relationship nor affect overall cycle length. This apparent finding is likely not due to the lower body weights as feed restriction has been shown to lengthen the estrous cycle.^75^ Given this, these discordant minimal responses in estrous cyclicity, independent of the delays in VO and BPS, were therefore considered equivocal evidence of developmental toxicity.

The only fetal finding observed that was attributed to EHMC exposure was the higher incidence of rudimental rib, a variation that exceeded the historical control incidence. This common fetal finding, in isolation, is not considered adverse. No delays in ossification were observed, unlike those that have been previously reported.^25^ Two of EHMC’s known metabolites, 2-ethylhexanol and 2-ethylhexanoic acid, have been shown to have teratogenic potential.^11^ Administration of 12.5 mM/kg of 2-ethylhexanol (approximately 1,680 g/kg) to Wistar rats on GD 12 was associated with hydronephrosis and tail and limb malformations. Administration of 2-ethylhexanoic acid at the same mM dose induced a greater response in these endpoints. Cardiovascular defects were also observed.^76^

Exposure of Wistar rats to 2-ethylhexanoic acid from GD 6 through GD 19 via drinking water at exposure concentrations of 100, 300, or 600 mg/kg/day was associated with fetal malformations of clubfoot, absence of fibula, and polydactyly.^77^ In contrast, topical application in Fischer 344 rats from GD 6 through GD 15 at exposure concentrations ≤2,520 mg/kg/day was not associated with any teratogenic responses.^78^ The absence of malformations in the current study may be the result of metabolites not being produced to an internal concentration that would affect normal fetal development.

EHMC exposure was associated with an increase in liver weight, but this finding was not coupled with any adverse histopathological findings. The weight increase might be a secondary response given that the liver is a major site of EHMC metabolism.