# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: h[underlined: ttps://doi.org/10.22427/NTP-DATA-DART-06].^72^

## Dose Range-finding Study

### Maternal Findings

#### Viability and Clinical Observations

In the dose range-finding study, one female in the 20,000 ppm group was euthanized on lactation day (LD) 15 due to excessive body weight loss and no surviving offspring. In addition, six females were euthanized on LD 4 and one female was euthanized on LD 14 because they had no surviving offspring (other dams were removed from the 0, 2,250, 5,000, and 20,000 ppm groups for scheduled biological sampling collection) (Appendix E). No clinical observations were attributed to 2-ethylhexyl p-methoxycinnamate (EHMC) in any exposure group (Appendix E).

#### Body Weights and Feed Consumption

On gestation day (GD) 21, the mean body weights of dams exposed to 20,000 ppm EHMC were significantly decreased by 22% relative to the control group (Table 4; Figure 5). This exposed group also displayed a transient loss in mean body weight over the GD 6–9 interval (loss of 3.4 g; control group gained 12.4 g) (Table 4). Maternal mean body weight gain between GD 6 and GD 21 in the 20,000 ppm group was significantly decreased by 68% relative to the control group (Table 4). LD 1 dam mean body weights of the 20,000 ppm group were significantly decreased by 20% relative to the control group (Table 4; Figure 5). Live litter size on postnatal day (PND) 0 was not affected by EHMC exposure (Appendix E); however, pup mean body weight on PND 1 of the 20,000 ppm group was significantly decreased by 39% relative to the control pup mean body weight, which also contributed to the reduction in maternal mean body weight gain observed during gestation (Table 4; Figure 5). During lactation, maternal mean body weights of dams exposed to ≤5,000 ppm were similar to those of the control group (Table 4; Figure 5). From LD 1 through LD 14, mean body weights of dams in the 20,000 ppm group were significantly decreased by 20%–37% compared to the control group mean body weights; the remaining dams in the 20,000 ppm group were removed from the study on LD 14 (Table 4).

Table 4 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Gestation and Lactation (Dose Range-finding Study)

Parameter^a,b^ | 0 ppm | 2,250 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Gestation Body Weight
Gestation Day
6 | 232.7 ± 4.0 (12) | 229.4 ± 2.6 (12) | 232.4 ± 3.9 (6) | 229.7 ± 3.5 (8) | 232.9 ± 3.5 (13)
9 | 245.0 ± 4.7** (12) | 243.1 ± 3.1 (12) | 247.5 ± 4.7 (6) | 237.9 ± 4.2 (8) | 229.5 ± 3.2** (13)
12 | 259.8 ± 5.0** (12) | 258.5 ± 3.0 (12) | 262.2 ± 4.7 (6) | 251.8 ± 5.1 (8) | 231.0 ± 3.0** (13)
15 | 278.1 ± 5.4** (12) | 277.5 ± 3.3 (12) | 280.3 ± 5.3 (6) | 272.5 ± 6.0 (8) | 239.3 ± 3.9** (13)
18 | 311.6 ± 6.3** (12) | 312.6 ± 4.8 (12) | 312.0 ± 5.7 (6) | 309.4 ± 7.6 (8) | 253.4 ± 4.4** (13)
21 | 339.7 ± 9.3** (9) | 344.2 ± 5.6 (9) | 350.0 ± 5.8 (6) | 343.4 ± 9.0 (7) | 265.9 ± 7.2** (10)
Gestation Weight Change
Gestation Day Interval
6–21 | 110.1 ± 8.1** (9) | 114.0 ± 5.5 (9) | 117.6 ± 3.7 (6) | 113.4 ± 6.5 (7) | 35.1 ± 8.0** (10)
6–9 | 12.4 ± 1.3** (12) | 13.8 ± 1.3 (12) | 15.2 ± 1.7 (6) | 8.2 ± 1.2* (8) | −3.4 ± 1.3** (13)
9–12 | 14.8 ± 0.8** (12) | 15.4 ± 0.7 (12) | 14.6 ± 1.4 (6) | 13.8 ± 1.5 (8) | 1.5 ± 1.3** (13)
12–15 | 18.3 ± 0.9** (12) | 19.0 ± 1.0 (12) | 18.1 ± 1.7 (6) | 20.8 ± 1.9 (8) | 8.4 ± 1.5** (13)
15–18 | 33.5 ± 2.8** (12) | 35.0 ± 2.4 (12) | 31.7 ± 1.5 (6) | 36.9 ± 2.2 (8) | 14.0 ± 1.7** (13)
18–21 | 32.8 ± 3.2* (9) | 34.7 ± 3.2 (9) | 38.0 ± 1.8 (6) | 36.1 ± 2.4 (7) | 17.7 ± 4.7* (10)
Lactation Body Weight
Lactation Day
1 | 254.7 ± 3.7** (8) | 249.4 ± 4.5 (9) | 255.2 ± 5.4 (6) | 247.5 ± 5.4 (8) | 203.7 ± 7.9** (8)
4 | 271.2 ± 5.6** (8) | 266.6 ± 3.8 (9) | 270.8 ± 4.4 (6) | 253.2 ± 6.8* (8) | 204.8 ± 6.4** (8)
7 | 275.8 ± 2.5* (5) | 270.3 ± 4.0 (6) | 276.3 ± 4.1 (6) | 261.2 ± 6.9 (6) | 193.5 ± 0.8** (2)
14 | 279.6 ± 6.3* (5) | 287.9 ± 4.8 (6) | 289.0 ± 5.7 (6) | 248.0 ± 13.0* (6) | 176.0 ± 4.2** (2)
21 | 272.7 ± 9.5 (5) | 278.3 ± 5.7 (6) | 284.8 ± 6.7 (6) | 234.0 ± 14.1* (6) | –^c^
Lactation Weight Change
Lactation Day Interval
1–21 | 17.0 ± 8.8 (5) | 26.5 ± 5.6 (6) | 29.6 ± 4.9 (6) | −13.4 ± 11.8 (6) | –^c^
1–4 | 16.5 ± 3.0** (8) | 17.1 ± 3.1 (9) | 15.5 ± 1.9 (6) | 5.6 ± 3.0* (8) | 1.1 ± 3.6** (8)
4–7 | 8.0 ± 2.2 (5) | 4.3 ± 7.7 (6) | 5.6 ± 6.0 (6) | 5.1 ± 2.9 (6) | −6.4 ± 1.9 (2)
7–14 | 3.8 ± 7.9* (5) | 17.6 ± 5.9 (6) | 12.7 ± 6.8 (6) | −13.2 ± 7.9 (6) | −17.5 ± 5.0 (2)
14–21 | −6.8 ± 11.6 (5) | −9.6 ± 2.5 (6) | −4.1 ± 7.9 (6) | −14.0 ± 9.5 (6) | –^c^

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (n); body weight data are presented in grams. Changes in n are the result of animal removal (i.e., biological sampling, animal health concerns).

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ The 20,000 ppm group was removed on lactation day 14 due to excessive body weight loss and no surviving offspring.

Figure 5

Growth Curves for F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Gestation and Lactation (Dose Range-finding Study)

Growth curves shown for F_0_ female rats during (A) gestation and (B) lactation. Information for statistical significance in maternal weights is provided in Table 4.

Feed consumption by the 20,000 ppm group appeared to be significantly decreased over the GD 9–12 and GD 15–18 intervals (Table 5)—approximately 25% lower than feed consumption by the control group, but suspected feed wastage (dams digging and spilling feed that could not be measured) decreased confidence in the accuracy of the respective EHMC feed consumption data, with actual feed consumption likely less than estimated from measures of feed remaining in the feed dispenser at the time of feed change. The actual feed consumption being lower than what was estimated might have contributed to the lower dam and pup mean body weights of the 20,000 ppm group. Feed consumption by the other EHMC groups was similar to that of the control group (Table 5). EHMC intake for F_0_ females in the 2,250, 5,000, 10,000, and 20,000 ppm groups, based on measured feed consumption and dietary concentrations for GD 6–21, was approximately 161, 365, 714, and 1,841 mg EHMC/kg body weight/day (mg/kg/day), respectively. Feed consumption by dams in the 20,000 ppm group between LD 4 and LD 7 was half that of the control group but represented only the two remaining dams with offspring (Table 5). LD 1 through LD 14 feed consumption by the 10,000 ppm group was approximately 83% that of the control group (Table 5), with the mean body weight significantly decreased at LD 4 and LD 14 (Table 4). EHMC intake for F_0_ females in the 2,250, 5,000, and 10,000 ppm EHMC groups, based on feed consumption and dietary concentrations for LD 1 through LD 14, was approximately 410, 925, and 1,615 mg/kg/day, respectively (Table 5).

Table 5 Summary of Feed and Test Article Consumption of F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Gestation and Lactation (Dose Range-finding Study)

Parameter^a,b,c^ | 0 ppm | 2,250 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Feed Consumption (g/animal/day)^d^
Gestation Day Interval
6–21 | 19.7 ± 0.8 (9) | 19.5 ± 0.4 (8) | 20.4 ± 0.7 (6) | 19.5 ± 1.0 (8) | 21.9 ± 1.5 (10)
3–6 | 17.8 ± 0.7 (12) | 17.3 ± 0.3 (12) | 18.0 ± 1.0 (6) | 16.7 ± 0.7 (8) | 17.3 ± 0.5 (13)
6–9 | 18.3 ± 0.7 (12) | 17.8 ± 0.4 (12) | 18.9 ± 0.9 (6) | 16.4 ± 1.9 (8) | 31.7 ± 2.9* (10)
9–12 | 19.1 ± 0.6** (12) | 18.8 ± 0.5 (12) | 19.2 ± 1.0 (6) | 17.7 ± 1.1 (8) | 13.8 ± 0.5** (13)
12–15 | 19.6 ± 0.7 (12) | 19.8 ± 0.6 (12) | 19.9 ± 1.0 (6) | 18.9 ± 1.2 (8) | 29.5 ± 3.4 (6)
15–18 | 22.1 ± 0.6** (12) | 21.8 ± 0.6 (12) | 21.3 ± 0.6 (6) | 23.0 ± 1.1 (8) | 17.3 ± 0.8** (13)
18–21 | 21.0 ± 0.9 (9) | 22.0 ± 0.8 (8) | 22.8 ± 0.6 (6) | 21.3 ± 1.0 (8) | 27.9 ± 5.9 (5)
Lactation Day Interval
1–14 | 49.8 ± 1.7 (5) | 48.8 ± 3.3 (6) | 50.5 ± 1.0 (6) | 41.5 ± 4.7 (5)^d^ | −^e,f^
1–4 | 33.7 ± 2.2 (8) | 33.8 ± 2.0 (9) | 32.3 ± 1.5 (6) | 30.4 ± 2.2 (8) | 38.2 ± 9.1 (4)
4–7 | 43.3 ± 1.2 (5) | 43.4 ± 3.9 (6) | 43.5 ± 1.1 (6) | 40.0 ± 2.3 (6) | 19.6 ± 1.1 (2)
7–14 | 60.3 ± 2.5 (5) | 57.6 ± 4.1 (6) | 61.2 ± 1.5 (6) | 46.9 ± 6.8 (5) | −^f^
Chemical Intake (mg/kg/day)^g,h^
GD 6–21 | 0 ± 0.0 (9) | 161.1 ± 3.5 (8) | 365.2 ± 10.1 (6) | 713.5 ± 29.0 (8) | 1,841.4 ± 125.7 (10)
LD 1–14 | 0 ± 0.0 (5) | 409.8 ± 31.1 (6) | 924.9 ± 14.1 (6) | 1,615.0 ± 125.6 (5)^e^ | −^e,f^

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ±standard error (n), where n = the number of dams. Feed consumption is not reported for nonpregnant animals during the gestation or lactation phase.

^b^ Changes in n are the result of animal removal (i.e., biological sampling, animal health concerns).

^c^ For each dam, calculation of consumption values for the GD 6–21 and LD 1–14 intervals was performed using all valid data for the animal, even if data were unavailable for some of the subintervals.

^d^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Consumption and chemical intake was omitted for animals with no recorded consumption during the LD 7–14 interval.

^f^ The 20,000 ppm group was removed on LD 14 due to excessive body weight loss and no surviving offspring.

^g^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^h^ No statistical analysis performed on the chemical intake data.

#### Maternal Reproductive Performance

EHMC did not affect the number of animals littering, with the possible exception of the 20,000 ppm group in which only 80% of the dams littered. Litter size on PND 0 was similar across all the exposure groups (Table 6).

Table 6 Summary of the Reproductive Performance of F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Gestation (Dose Range-finding Study)

Parameter^a^ | 0 ppm | 2,250 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Time-mated Females (GD 6) | 14^b^ | 14^b^ | 8 | 8 | 14^b^
Females Pregnant (%) | 12 (85.7) | 12 (85.7) | 6 (75.0) | 8 (100.0) | 13 (92.9)
Females Not Pregnant (%) | 2 (14.3) | 2 (14.3) | 2 (25.0) | 0 (0.0) | 1 (7.1)
Dams Removed on GD 18^c^ | 3 | 3 | 0 | 0 | 3
Dams Not Delivering with Evidence of Pregnancy (%) | 1 (11.1) | 0 (0.0) | 0 (0.0) | 0 (0.0) | 2 (20.0)
Dams with Litters on PND 0 (%)^d^ | 8 (88.9) | 9 (100.0) | 6 (100.0) | 8 (100.0) | 8 (80.0)
Gestation Length (days)^e,f,g^ | 22.0 ± 0.0 (8) | 22.3 ± 0.2 (9) | 22.2 ± 0.2 (6) | 21.9 ± 0.1 (8) | 22.3 ± 0.2 (8)
Live Litter Size on PND 0^e,g^ | 11.9 ± 1.0 (8) | 11.7 ± 1.0 (9) | 11.8 ± 0.5 (6) | 13.6 ± 0.8 (8) | 11.1 ± 0.9 (8)
PND 1 Pup Weight^g,h,i^ | 6.90 ± 0.11** 8 (94) | 6.78 ± 0.16 9 (104) | 7.10 ± 0.25 6 (70) | 6.62 ± 0.15 8 (108) | 4.19 ± 0.41** 6 (47)
Percent Live Male Pups/Litter^e,g^ | 63.07 ± 4.75* (8) | 50.25 ± 5.68 (9) | 53.14 ± 4.23 (6) | 51.09 ± 6.86 (8) | 44.22 ± 5.53* (8)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; PND = postnatal day.

^a^ Animals removed from study between mating and littering excluded from calculations of % littered females.

^b^ Includes six time-mated (pregnant) rats used for biological sample collection for methods development.

^c^ Dams removed on GD 18 for biological sample collection.

^d^ Percentage is the number of littered females/pregnant females. Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^e^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ Gestation length calculated for time-mated females that delivered a litter.

^g^ Data are displayed as mean ± standard error (n).

^h^ n = the number of litters examined (number of pups).

^i^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

### F_1_ Offspring Findings

#### Pup Viability and Body Weights

EHMC exposure was associated with fewer live pups per litter in the 20,000 ppm group (approximately four pups per litter) on PND 1 than in the control group; by PND 4, an average of 7.5 pups per litter were alive in the 20,000 ppm group (Table 7). In contrast, average live PND 4 litter size in the control group was 11.8. Live litter size and survival ratios of the other EHMC-exposed groups were similar to those of the control group (Table 7). Over the lactation period (PND 1 through PND 28), there were nine dead/euthanized pups (from three litters) in the 10,000 ppm group and 89 dead/euthanized pups (from eight litters) in the 20,000 ppm group, compared to zero dead/euthanized pups in the control group (Appendix E). In the 5,000 and 2,250 ppm groups, one pup was found dead and two pups (from two litters) were euthanized, respectively (Appendix E).

Table 7 Summary of F_1_ Litter Size and Pup Survival Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate (Dose Range-finding Study)

Postnatal Day | 0 ppm | 2,250 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
No. of Live Pups (Litters)^a^
0 | 95 (8) | 105 (9) | 71 (6) | 109 (8) | 89 (8)
Total Litter Size^b,c^
0 | 12.3 ± 1.0 (8) | 12.6 ± 1.4 (9) | 11.8 ± 0.5 (6) | 13.8 ± 0.9 (8) | 12.4 ± 0.8 (8)
Live Litter Size^b,c^
0 | 11.9 ± 1.0 (8) | 11.7 ± 1.0 (9) | 11.8 ± 0.5 (6) | 13.6 ± 0.8 (8) | 11.1 ± 0.9 (8)
1 | 11.8 ± 0.9 (8) | 11.6 ± 1.1 (9) | 11.7 ± 0.6 (6) | 13.5 ± 0.8 (8) | 7.8 ± 1.2 (6)
4^d^ | 11.8 ± 0.9 (8) | 11.6 ± 1.1 (9) | 11.7 ± 0.6 (6) | 13.4 ± 0.8 (8) | 7.5 ± 1.5 (2)
7 | 11.0 ± 0.7 (5) | 11.2 ± 1.6 (6) | 11.7 ± 0.6 (6) | 13.0 ± 0.7 (6) | 7.5 ± 1.5 (2)
14 | 11.0 ± 0.7 (5) | 11.0 ± 1.5 (6) | 11.7 ± 0.6 (6) | 12.0 ± 0.7 (6) | 6.0 (1)
21 | 11.0 ± 0.7 (5) | 11.0 ± 1.5 (6) | 11.7 ± 0.6 (6) | 12.0 ± 0.7 (6) | –^e^
28 | 11.0 ± 0.7 (5) | 11.0 ± 1.5 (6) | 11.7 ± 0.6 (6) | 12.0 ± 0.7 (6) | –^e^
No. of Dead Pups (Litters)^a^
0 | 3 (2) | 8 (3) | 0 (0) | 1 (1) | 10 (5)
1–4 | 1 (1) | 1 (1) | 1 (1) | 2 (2) | 74 (7)
5–28 | 0 (0) | 1 (1) | 0 (0) | 8 (2) | 15 (2)
Dead per Litter^b,c^
0 | 0.38 ± 0.26 (8) | 0.89 ± 0.65 (9) | 0.00 ± 0.00 (6) | 0.13 ± 0.13 (8) | 1.25 ± 0.45 (8)
1–4 | 0.13 ± 0.13** (8) | 0.11 ± 0.11 (9) | 0.17 ± 0.17 (6) | 0.25 ± 0.16 (8) | 9.25 ± 1.96** (8)
5–28 | 0.00 ± 0.00** (5) | 0.17 ± 0.17 (6) | 0.00 ± 0.00 (6) | 1.33 ± 0.88 (6) | 7.50 ± 1.50** (2)
1–28 | 0.00 ± 0.00** (5) | 0.33 ± 0.21 (6) | 0.17 ± 0.17 (6) | 1.50 ± 0.85 (6) | 11.13 ± 0.90** (8)
Live Birth Ratio^b,c^
0 | 0.97 ± 0.02 (8) | 0.95 ± 0.03 (9) | 1.00 ± 0.00 (6) | 0.99 ± 0.01 (8) | 0.89 ± 0.04 (8)
Survival Ratio^b,c^
0 | 0.97 ± 0.02 (8) | 0.95 ± 0.03 (9) | 1.00 ± 0.00 (6) | 0.99 ± 0.01 (8) | 0.89 ± 0.04 (8)
1–4 | 0.99 ± 0.01** (8) | 0.99 ± 0.01 (9) | 0.98 ± 0.02 (6) | 0.98 ± 0.01 (8) | 0.24 ± 0.16** (8)
5–28 | 1.00 ± 0.00** (5) | 0.99 ± 0.01 (6) | 1.00 ± 0.00 (6) | 0.91 ± 0.06 (6) | 0.00 ± 0.00** (2)
1–28 | 1.00 ± 0.00** (5) | 0.97 ± 0.02 (6) | 0.98 ± 0.02 (6) | 0.90 ± 0.06 (6) | 0.00 ± 0.00** (8)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ n = the number of pups (number of litters).

^b^ Data are displayed as mean ± standard error of the litter means (n), where n = number of litters.

^c^ F_1_ litter size and survival endpoints were analyzed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests. All calculations are based on the last litter observation of the day.

^d^ Up to three dams and their litters in the 0, 2,250, 10,000, and 20,000 ppm groups were removed for biological sample collection on postnatal day 4.

^e^ The 20,000 ppm group was removed on postnatal day 14 due to pup moribundity and mortality.

Male and female pup body weights of the 10,000 and 20,000 ppm groups were significantly decreased (16%–76%) relative to the control groups at most time points (Table 8; Figure 6, Figure 7). After PND 14, male and female pups in the 5,000 ppm group displayed slightly lower body weights (approximately 15%) (Table 8). Adverse F_1_ pup clinical observations in the 10,000 and 20,000 ppm groups were consistent with the effects of EHMC exposure on pup survival (Appendix E). Findings included observations of pups found dead, cannibalized or missing, no milk in the stomach, and emaciated. There were no notable gross findings in the F_1_ offspring examined. Necropsy findings for pups found dead on or after PND 1 were limited to absence of milk/food in the stomach (Appendix E).

Table 8 Summary of F_1_ Male and Female Pup Mean Body Weights and Body Weight Gains Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate (Dose Range-finding Study)^a,b^

Postnatal Day^c^ | 0 ppm | 2,250 ppm | 5,000 ppm | 10,000 ppm | 20,000 ppm
Male
1 | 7.00 ± 0.11** 58 (8)^d^ | 6.83 ± 0.18 50 (9) | 7.35 ± 0.28 37 (6) | 6.79 ± 0.16 55 (8) | 4.42 ± 0.35** 18 (5)
4 | 10.41 ± 0.14** 58 (8) | 10.08 ± 0.29 50 (9) | 10.59 ± 0.27 37 (6) | 9.48 ± 0.28 54 (8) | 4.97 ± 0.71** 14 (4)
7 | 15.16 ± 0.37** 36 (5) | 14.79 ± 0.54 28 (6) | 14.58 ± 0.30 37 (6) | 12.77 ± 0.64** 34 (6) | 6.60 ± 0.46** 5 (2)
14 | 29.79 ± 0.97** 36 (5) | 27.87 ± 0.29 27 (6) | 26.08 ± 0.67 37 (6) | 20.03 ± 1.60** 32 (6) | 7.04 ± 1.06** 5 (2)
21 | 44.34 ± 1.53** 36 (5) | 42.16 ± 1.33 27 (6) | 37.84 ± 1.07 37 (6) | 24.01 ± 2.81** 32 (6) | −^e^
28 | 76.84 ± 2.50** 36 (5) | 73.13 ± 2.00 27 (6) | 67.00 ± 2.26 37 (6) | 36.83 ± 4.40** 32 (6) | −^e^
1–28^f^ | 69.84 ± 2.48** 36 (5) | 66.16 ± 2.06 27 (6) | 59.67 ± 2.05 37 (6) | 30.13 ± 4.27** 32 (6) | −^e^
Female
1 | 6.67 ± 0.12** 36 (8) | 6.71 ± 0.17 54 (9) | 6.77 ± 0.24 33 (6) | 6.37 ± 0.17 53 (8) | 4.29 ± 0.39** 29 (6)
4 | 10.01 ± 0.10** 36 (8) | 9.96 ± 0.30 54 (9) | 9.78 ± 0.29 33 (6) | 8.93 ± 0.28* 53 (8) | 5.06 ± 0.69** 22 (4)
7 | 14.96 ± 0.30** 19 (5) | 14.88 ± 0.87 39 (6) | 13.31 ± 0.46 33 (6) | 11.73 ± 0.57** 43 (6) | 7.59 ± 0.52** 10 (2)
14 | 29.22 ± 0.94** 19 (5) | 27.75 ± 1.35 39 (6) | 24.46 ± 0.76* 33 (6) | 18.46 ± 1.26** 40 (6) | 7.68 ± 0.76** 10 (2)
21 | 41.04 ± 2.01** 19 (5) | 42.17 ± 2.92 39 (6) | 35.47 ± 1.32 33 (6) | 21.89 ± 2.09** 40 (6) | −^e^
28 | 72.90 ± 1.92** 18 (5) | 69.33 ± 4.07 39 (6) | 60.85 ± 2.50* 33 (6) | 33.93 ± 3.29** 40 (6) | −^e^
1–28^f^ | 66.14 ± 1.80** 18 (5) | 62.46 ± 3.93 39 (6) | 54.13 ± 2.32* 33 (6) | 27.63 ± 3.18** 40 (6) | −^e^
Male and Female
1 | 6.90 ± 0.11** 94 (8) | 6.78 ± 0.16 104 (9) | 7.10 ± 0.25 70 (6) | 6.62 ± 0.15 108 (8) | 4.19 ± 0.41** 47 (6)
4 | 10.23 ± 0.11** 94 (8) | 9.99 ± 0.28 104 (9) | 10.22 ± 0.28 70 (6) | 9.21 ± 0.27* 107 (8) | 5.01 ± 0.69** 36 (4)
7 | 15.00 ± 0.33** 55 (5) | 14.70 ± 0.60 67 (6) | 14.00 ± 0.37 70 (6) | 12.25 ± 0.56** 77 (6) | 7.06 ± 0.42** 15 (2)
14 | 29.41 ± 0.91** 55 (5) | 27.48 ± 0.72 66 (6) | 25.33 ± 0.71* 70 (6) | 19.32 ± 1.40** 72 (6) | 7.20 ± 0.76** 15 (2)
21 | 42.64 ± 1.57** 55 (5) | 41.81 ± 1.90 66 (6) | 36.69 ± 1.18 70 (6) | 23.02 ± 2.48** 72 (6) | −^e^
28 | 75.36 ± 2.33** 54 (5) | 70.38 ± 2.93 66 (6) | 64.05 ± 2.30* 70 (6) | 35.70 ± 3.93** 72 (6) | −^e^
1–28^f^ | 68.44 ± 2.25** 54 (5) | 63.50 ± 2.87 66 (6) | 57.01 ± 2.11* 70 (6) | 29.20 ± 3.82** 72 (6) | −^e^

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^b^ Data are displayed as mean ± standard error of the litter means. Body weight data are presented in grams.

^c^ As litters were not standardized, pup weights throughout the entire postnatal period were adjusted using the total live litter size on postnatal day (PND) 1.

^d^ n = the number of pups examined (number of litters).

^e^ The 20,000 ppm group was removed on PND 14 due to pup moribundity and mortality.

^f^ Body weight gain (data are presented in grams).

Figure 6

Lactation Growth Curves for F_1_ Male Pups Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate (Dose Range-finding Study)

Information for statistical significance in male pup weights is provided in Table 8.

Figure 7

Lactation Growth Curves for F_1_ Female Pups Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate (Dose Range-finding Study)

Information for statistical significance in female pup weights is provided in Table 8.

### Exposure Concentration Selection Rationale for the Modified One-Generation Study of 2-Ethylhexyl p-Methoxycinnamate

Selection of 6,000 ppm as the highest exposure concentration for the modified one-generation (MOG) study was based on excessively lower pup mean body weight observed at the 10,000 ppm exposure concentration for the dose range-finding study. Compared to the control group on PND 28, relative pup body weights of dams exposed to 5,000 ppm were lower for both females (17%, significant) and males (13%), approximating the targeted 10% reduction to ensure a challenge recognizing the limited sample size (Table 8). Exposure concentration spacing for the MOG study (1,000, 3,000, and 6,000 ppm) was selected to achieve an ideal no-observed-adverse-effect level and to avoid excessive exposure overlap due to higher feed consumption during pregnancy and lactation.

## Modified One-Generation Study

### F_0_ Generation: Maternal Findings

Maternal effects were evaluated from GD 6 through LD 28, as shown in Figure 8. Viability, clinical observations, gestation and lactation mean body weights, feed consumption, and reproductive performance results are presented below.

Figure 8

Design of the Modified One-Generation Study–F_0_ Generation

GD = gestation day; LD = lactation day; PND = postnatal day.

#### F_0_ Viability and Clinical Observations

EHMC exposure did not affect viability of the F_0_ females (Appendix E). One female in the 6,000 ppm group was removed on study day 8 with exophthalmos and a head tilt; histopathology revealed retinal atrophy. Due to the timing of the lesion, and given this was an isolated case, the observation was not considered related to EHMC exposure. No clinical observations were attributed to EHMC exposure (Appendix E).

#### F_0_ Gestation Body Weights and Feed Consumption

F_0_ females exposed to EHMC displayed similar mean body weights and body weight gains throughout gestation as the control group (Table 9; Figure 9). EHMC exposure did not adversely affect feed consumption during gestation (Table 10). EHMC intake based on feed consumption and dietary concentrations during gestation (F_0_ [Table 10] and both F_1_ cohorts [Appendix E]) was similar to postweaning intake by both sexes (Appendix E), with intake ranging from 70 to 87, 207 to 263, and 419 to 528 mg/kg/day by the 1,000, 3,000 and 6,000 ppm groups, respectively. EHMC intake was similar during the early lactational period of both generations and was approximately twofold greater than it was during the other periods (Appendix E).

Table 9 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Gestation

Parameter^a,b^ | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Gestation Body Weight
Gestation Day
6 | 241.9 ± 2.5 (22) | 242.0 ± 2.5 (24) | 239.6 ± 2.7 (19) | 239.5 ± 3.2 (22)
9 | 254.5 ± 2.6 (22) | 254.2 ± 2.2 (24) | 252.1 ± 2.8 (19) | 251.8 ± 2.4 (22)
12 | 269.1 ± 2.8 (22) | 269.9 ± 2.2 (24) | 266.1 ± 2.8 (19) | 267.9 ± 2.3 (22)
15 | 287.1 ± 3.0 (22) | 288.9 ± 2.4 (24) | 284.3 ± 3.2 (19) | 286.0 ± 2.7 (22)
18 | 322.3 ± 3.4 (22) | 329.1 ± 2.9 (24) | 321.7 ± 3.7 (19) | 322.8 ± 3.8 (22)
21 | 359.6 ± 4.4 (22) | 370.0 ± 3.9 (24) | 360.8 ± 4.5 (19) | 360.2 ± 4.6 (22)
Gestation Weight Change
Gestation Day Interval
6–21 | 117.7 ± 3.5 (22) | 128.0 ± 3.2 (24) | 121.2 ± 3.3 (19) | 120.7 ± 2.7 (22)
3–6 | 13.7 ± 1.4 (22) | 13.6 ± 1.8 (24) | 11.1 ± 1.2 (19) | 11.9 ± 2.1 (22)
6–9 | 12.6 ± 0.7 (22) | 12.2 ± 0.8 (24) | 12.6 ± 0.6 (19) | 12.3 ± 1.4 (22)
9–12 | 14.6 ± 0.7 (22) | 15.7 ± 0.7 (24) | 13.9 ± 0.7 (19) | 16.0 ± 0.7 (22)
12–15 | 18.0 ± 0.9 (22) | 19.0 ± 0.6 (24) | 18.3 ± 0.9 (19) | 18.1 ± 0.8 (22)
15–18 | 35.3 ± 1.3 (22) | 40.2 ± 1.2* (24) | 37.3 ± 1.1 (19) | 36.8 ± 1.4 (22)
18–21 | 37.2 ± 1.5 (22) | 40.9 ± 1.6 (24) | 39.1 ± 1.9 (19) | 37.4 ± 1.3 (22)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05.

^a^ Data are displayed as mean ± standard error (n); body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

Figure 9

Growth Curves for F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Gestation

Information for statistical significance in maternal weights is provided in Table 9.

Table 10 Summary of Feed and Test Article Consumption of F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Gestation

Gestation Day Interval^a,b^ | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Feed Consumption (g/animal/day)^c^
6–21 | 20.2 ± 0.4 (22) | 20.2 ± 0.2 (24) | 19.7 ± 0.3 (19) | 19.9 ± 0.3 (21)
3–6 | 17.8 ± 0.4 (22) | 17.2 ± 0.3 (24) | 17.2 ± 0.4 (19) | 17.6 ± 0.3 (21)
6–9 | 18.4 ± 0.5** (22) | 18.2 ± 0.2 (24) | 17.6 ± 0.4 (19) | 16.8 ± 0.4** (21)
9–12 | 18.9 ± 0.5 (22) | 18.8 ± 0.2 (24) | 17.8 ± 0.5 (19) | 18.9 ± 0.3 (21)
12–15 | 19.8 ± 0.5 (22) | 19.8 ± 0.2 (24) | 19.1 ± 0.5 (19) | 19.6 ± 0.4 (21)
15–18 | 21.8 ± 0.5 (22) | 22.5 ± 0.4 (24) | 22.1 ± 0.3 (19) | 22.3 ± 0.5 (22)
18–21 | 22 ± 0.6 (22) | 21.8 ± 0.5 (24) | 21.9 ± 0.4 (19) | 22.2 ± 0.4 (22)
Chemical Intake (mg/kg/day)^d,e^
6–21 | 0.0 ± 0.0 (22) | 69.6 ± 0.6 (24) | 207.2 ± 3.4 (19) | 418.7 ± 6.9 (21)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n), where n = the number of dams. Feed consumption is not reported for nonpregnant animals during the gestation phase.

^b^ For each dam, calculation of consumption values for the GD 6–21 interval was performed using all valid data for the animal, even if data were unavailable for some of the subintervals.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^e^ No statistical analysis performed on the chemical intake data.

#### Maternal Reproductive Performance

Across all exposure groups, 17 of 104 time-mated rats were not pregnant (Table 11; Appendix E). There was no effect of EHMC exposure on the proportion of dams that produced viable litters, or on gestation length (Table 11). PND 0 litter size was slightly, but significantly, increased in the 1,000 ppm group relative to the control group, which was considered incidental and likely the result of the control group litter size being slightly lower than expected (Table 11). Litter sizes among all other groups were similar. There was no effect of EHMC exposure on PND 1 pup weight or sex ratio (Table 11).

Table 11 Summary of the Reproductive Performance of F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Gestation

Parameter^a^ | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Time-mated Females (GD 6) | 26 | 26 | 26 | 26
Females Pregnant (%) | 22 (84.6) | 24 (92.3) | 19 (73.1) | 22 (84.6)
Females Not Pregnant (%) | 4 (15.4) | 2 (7.7) | 7 (26.9) | 4 (15.4)
Dams with Litters on PND 0 (%)^b^ | 22 (100.0) | 24 (100.0) | 19 (100.0) | 22 (100.0)
Gestation Length (days)^c,d,e^ | 22.0 ± 0.0 (22) | 22.0 ± 0.0 (24) | 21.9 ± 0.1 (19) | 22.1 ± 0.1 (22)
Live Litter Size on PND 0^c,e^ | 10.8 ± 0.7 (22) | 13.0 ± 0.4* (24) | 11.7 ± 0.4 (19) | 11.1 ± 0.7 (22)
PND 1 Pup Weight^e,f,g^ | 6.90 ± 0.07 235 (22) | 6.89 ± 0.08 311 (24) | 6.91 ± 0.07 221 (19) | 7.01 ± 0.09 244 (22)
Percent Live Male Pups/Litter^c,e^ | 57.11 ± 3.34 (22) | 48.94 ± 2.94 (24) | 49.98 ± 2.55 (19) | 49.80 ± 3.27 (22)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05.

GD = gestation day; PND = postnatal day.

^a^ Animals removed from the study between mating and littering were excluded from calculations of % littered females.

^b^ Percentage is the number of littered females/pregnant females. Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ Gestation length was calculated for time-mated females that delivered a litter.

^e^ Data are displayed as mean ± standard error (n).

^f^ n = the number of pups examined (number of litters).

^g^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

#### Lactation Body Weights and Feed Consumption

F_0_ females exposed to EHMC displayed similar mean body weights and body weight gains throughout most of lactation (Table 12; Figure 10). On LD 10 and LD 13 the mean body weights of the 6,000 ppm group were slightly but significantly decreased and were lower on LD 16 (approximately 3%, negative trend) relative to the control group and were preceded by slightly but significantly decreased (approximately 6%, negative trend) feed consumption over the LD 7–10 interval (Appendix E). These lower weights, although small in magnitude, occurred concomitantly with lower pup weights (Appendix E).

Table 12 Summary of Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Lactation^a^

Lactation Day | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Body Weight (g)^b^
1 | 267.9 ± 4.4 (22) | 265.4 ± 3.9 (24) | 265.2 ± 3.2 (19) | 262.4 ± 3.6 (22)
10 | 303.4 ± 3.3** (21) | 300.7 ± 2.8 (24) | 295.5 ± 3.4 (19) | 293.1 ± 2.3* (22)
13 | 306.6 ± 3.1* (21) | 303.4 ± 2.5 (24) | 301.5 ± 3.2 (19) | 295.6 ± 2.7* (22)
16 | 305.4 ± 3.4* (21) | 305.4 ± 2.5 (24) | 304.6 ± 3.0 (19) | 296.6 ± 2.6 (22)
28 | 283.1 ± 3.3 (21) | 283.5 ± 2.9 (24) | 280.4 ± 3.1 (19) | 282.7 ± 2.3 (22)
Body Weight Gain (g)^b^
1–28 | 15.2 ± 3.0 (21) | 18.1 ± 3.2 (24) | 15.2 ± 2.7 (19) | 20.3 ± 2.5 (22)
Feed Consumption^c^
1–13 (g/animal/day) | 45.2 ± 1.3* (21) | 46.2 ± 0.7 (24) | 44.9 ± 0.7 (19) | 43.3 ± 1.1 (21)
1–13 (g/kg/day) | 156.4 ± 4.6 (21) | 161.2 ± 2.7 (24) | 158.3 ± 2.7 (19) | 153.4 ± 4.0 (21)
Chemical Intake (mg/kg/day)^d,e^
1–13 | 0 ± 0.0 (21) | 161.2 ± 2.7 (24) | 474.8 ± 8.2 (19) | 920.2 ± 24.2 (21)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n), where n = the number of dams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^e^ No statistical analysis performed on the chemical intake data.

Figure 10

Growth Curves for F_0_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Lactation

Information for statistical significance in maternal weights is provided in Table 12.

### F_1_ Generation: Preweaning

F_1_ male and female rats were evaluated during the preweaning period from PND 0 through PND 28, as shown in Figure 11. Viability, clinical observations, and mean body weight results are presented below.

Figure 11

Design of the Modified One-Generation Study–F_1_ Generation: Preweaning

GD = gestation day; LD = lactation day; PND = postnatal day.

#### F_1_ Viability and Clinical Observations

Clinical observations noted for individual pups from all groups, including the control group, typically were indicative of an individual pup not thriving and included being cold to the touch and no milk in the stomach (Appendix E). Dams in the 1,000 ppm group had significantly increased total and live litter sizes on PND 0–4 relative to the control group (approximately two pups) (Table 13). Given the small magnitude of response and absence of an exposure concentration-response trend, it was not considered related to EHMC exposure. Given the larger PND 0 litter size in the 1,000 ppm group, litter size for that group was slightly larger for the first week of lactation. There was no observed effect of EHMC on pup survival (Table 13).

Table 13 Summary of F_1_ Litter Size and Pup Survival Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate

Postnatal Day | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
No. of Live Pups (Litters)^a^
0 | 246 (22) | 317 (24) | 230 (19) | 249 (22)
Total Litter Size^b,c^
0 | 11.2 ± 0.7 (22) | 13.2 ± 0.4* (24) | 12.1 ± 0.4 (19) | 11.3 ± 0.7 (22)
Live Litter Size^b,c^
0 | 10.8 ± 0.7 (22) | 13.0 ± 0.4* (24) | 11.7 ± 0.4 (19) | 11.1 ± 0.7 (22)
1 | 10.7 ± 0.7 (22) | 13.0 ± 0.4* (24) | 11.6 ± 0.4 (19) | 11.1 ± 0.7 (22)
4 (prestandardization) | 10.7 ± 0.7 (21) | 12.9 ± 0.4* (24) | 11.5 ± 0.4 (19) | 10.9 ± 0.7 (22)
4 (poststandardization) | 8.9 ± 0.4 (21) | 9.9 ± 0.1 (24) | 9.8 ± 0.2 (19) | 9.1 ± 0.4 (22)
13 | 8.9 ± 0.4 (21) | 9.7 ± 0.1 (24) | 9.8 ± 0.2 (19) | 8.9 ± 0.4 (22)
21 | 8.9 ± 0.4 (21) | 9.7 ± 0.1 (24) | 9.8 ± 0.2 (19) | 8.9 ± 0.4 (22)
28 | 8.9 ± 0.4 (21) | 9.7 ± 0.1 (24) | 9.7 ± 0.2 (19) | 8.9 ± 0.4 (22)
No. of Dead Pups (Litters)^a^
0 | 9 (6) | 5 (5) | 8 (6) | 4 (3)
1–4 | 12 (4) | 3 (3) | 3 (3) | 5 (5)
5–28 | 1 (1) | 4 (3) | 1 (1) | 5 (4)
Dead per Litter^b,c^
0 | 0.41 ± 0.16 (22) | 0.21 ± 0.08 (24) | 0.42 ± 0.18 (19) | 0.18 ± 0.11 (22)
1–4 | 0.55 ± 0.37 (22) | 0.13 ± 0.07 (24) | 0.16 ± 0.09 (19) | 0.23 ± 0.09 (22)
5–28 | 0.05 ± 0.05 (21) | 0.17 ± 0.10 (24) | 0.05 ± 0.05 (19) | 0.23 ± 0.11 (22)
Survival Ratio^b,c^
0 | 0.96 ± 0.02 (22) | 0.98 ± 0.01 (24) | 0.97 ± 0.01 (19) | 0.98 ± 0.01 (22)
1–4 | 0.94 ± 0.05 (22) | 0.99 ± 0.01 (24) | 0.99 ± 0.01 (19) | 0.98 ± 0.01 (22)
5–28 | 0.99 ± 0.01 (21) | 0.98 ± 0.01 (24) | 0.99 ± 0.01 (19) | 0.97 ± 0.01 (22)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05.

^a^ n = the number of pups examined (number of litters).

^b^ Data are displayed as mean ± standard error of the litter means (n), where n = the number of litters. For F_1_ pups, data are displayed as the mean of litter values ± standard error (n) of litter values (number of litters produced by F_0_ dams).

^c^ F_1_ litter size and survival endpoints were analyzed using the Jonckheere (trend) and Shirley or Dunn tests (pairwise comparisons). All calculations were based on the last litter observation of the day.

#### F_1_ Body Weights

##### Male Pups

An exposure concentration- and time-related reduction in male pup mean body weights per litter was observed in the groups exposed to 3,000 or 6,000 ppm EHMC relative to the control group (Table 14; Figure 12). On PND 28, male pup mean body weights per litter in the 3,000 and 6,000 ppm groups significantly decreased by 5% and 13%, respectively, relative to the control group. After the PND 4–7 interval, mean body weight gains in all subsequent intervals were significantly decreased in the 6,000 ppm group compared to the control group (Table 14; Appendix E). Mean body weight gains over the PND 13–16 interval were also significantly decreased in the 3,000 ppm group relative to the control group (Appendix E). Over the poststandardization PND 4–28 interval, male pups in the 3,000 and 6,000 ppm groups displayed significant decreases of 6% and 15%, respectively, relative to the mean body weight gains of the control group (Table 14).

Table 14 Summary of F_1_ Male and Female Pup Mean Body Weights and Body Weight Gains Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate^a,b^

Postnatal Day | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Male
1 | 6.96 ± 0.08 131 (22)^c^ | 7.01 ± 0.09 153 (24) | 7.05 ± 0.08 110 (19) | 7.17 ± 0.11 120 (22)
4^d^ | 10.14 ± 0.18 126 (21) | 10.07 ± 0.15 151 (24) | 10.23 ± 0.16 109 (19) | 10.25 ± 0.17 118 (22)
7 | 15.39 ± 0.30 100 (21) | 14.96 ± 0.30 115 (24) | 15.38 ± 0.27 91 (19) | 14.94 ± 0.23 97 (22)
13 | 28.78 ± 0.45** 100 (21) | 27.90 ± 0.42 115 (24) | 27.66 ± 0.58 91 (19) | 25.94 ± 0.34** 95 (22)
28 | 82.66 ± 1.00** 100 (21) | 82.13 ± 1.07 114 (24) | 78.92 ± 0.94* 91 (19) | 71.92 ± 0.90** 95 (22)
4–28^e^ | 72.46 ± 0.87** 100 (21) | 72.08 ± 0.97 114 (24) | 68.36 ± 0.85** 91 (19) | 61.60 ± 0.88** 95 (22)
Female
1 | 6.65 ± 0.07 104 (21) | 6.64 ± 0.08 158 (24) | 6.63 ± 0.07 111 (19) | 6.69 ± 0.09 124 (22)
4^d^ | 9.41 ± 0.32 101 (21) | 9.33 ± 0.14 158 (24) | 9.38 ± 0.13 110 (19) | 9.38 ± 0.16 122 (22)
7 | 14.39 ± 0.35 86 (20) | 13.75 ± 0.31 122 (24) | 13.95 ± 0.29 95 (19) | 13.60 ± 0.23 102 (22)
13 | 27.15 ± 0.47** 86 (20) | 25.99 ± 0.41 119 (24) | 24.95 ± 0.48** 95 (19) | 23.82 ± 0.32** 101 (22)
28 | 75.37 ± 1.11** 86 (20) | 73.63 ± 1.03 119 (24) | 69.81 ± 1.03** 95 (19) | 64.17 ± 0.87** 101 (22)
4–28^e^ | 65.75 ± 0.98** 86 (20) | 64.31 ± 0.96 119 (24) | 60.22 ± 0.95** 95 (19) | 54.87 ± 0.81** 101 (22)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons. Pup weights were adjusted for covariate litter size: total live on postnatal day (PND) 1 for day 1 to day 4 and number of live pups poststandardization for later days.

^b^ Data are displayed as mean ± standard error of the litter means. Body weights are presented in grams.

^c^ n = the number of pups examined (number of litters).

^d^ PND 4 weights are prestandardization.

^e^ Body weight gain (data are presented in grams).

Figure 12

Lactation Growth Curves for F_1_ Male Pups Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate

Information for statistical significance in male pup weights is provided in Table 14.

##### Female Pups

An exposure concentration- and time-related reduction in female pup mean body weights per litter was observed in the groups exposed to 3,000 or 6,000 ppm EHMC relative to the control group (Table 14; Figure 13). On PND 28, female pup mean body weights per litter in the 3,000 and 6,000 ppm groups significantly decreased by 7% and 15%, respectively, relative to the control group. Except for the PND 21–25 interval, mean body weight gains of female pups were significantly decreased in the 6,000 ppm group compared to the control group, starting at the PND 7–10 interval (Appendix E). Mean body weight gains were also significantly decreased in the 3,000 ppm group compared to the control group for the PND 7–10, 10–13, and 13–16 intervals (Appendix E). Over the poststandardization PND 4–28 interval, female pups exposed to 3,000 or 6,000 ppm displayed mean body weight gains that significantly decreased by 8% and 17%, respectively, relative to the control group (Table 14).

Figure 13

Lactation Growth Curves for F_1_ Female Pups Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate

Information for statistical significance in female pup weights is provided in Table 14.

#### F_0_ Necropsy

F_0_ females were necropsied on LD 28 following pup weaning, when the F_0_ females were 15–21 weeks of age. No gross or histological findings were associated with exposure to EHMC (Appendix E). The only finding observed was retinal atrophy in one animal. Given the singular occurrence, it was not attributed to EHMC exposure (Appendix E).

### F_1_ Generation: Postweaning through Sexual Maturity

F_1_ male and female rats were evaluated from postweaning through sexual maturity, as shown in Figure 14. Viability, clinical observations, mean body weights, feed consumption, and developmental endpoint results are presented below.

Figure 14

Design of the Modified One-Generation Study–F_1_ Generation: Postweaning

GD = gestation day; LD = lactation day; PND = postnatal day.

#### F_1_ Viability and Clinical Observations

EHMC exposure did not alter viability in the F_1_ generation. Clinical observations were noted in all groups, including the control groups, on a sporadic basis. No clinical observations showed an increase in incidence or severity in association with exposure to EHMC (Appendix E).

#### F_1_ Body Weights and Feed Consumption

##### Males (Postweaning)

The mean body weights of males in the 6,000 ppm group between PND 28 and PND 105 significantly decreased (5%–12%) relative to the control group (Table 15; Figure 15). In the 3,000 ppm group, mean body weights on PND 28 significantly decreased by approximately 7%, relative to the control group, and the PND 35–42 weight gain interval significantly decreased relative to the control group; however, for most of the rest of the study, mean body weights and body weight gains of the 3,000 ppm group did not differ significantly from the control group (Table 15; Appendix E).

Table 15 Summary of Postweaning Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of All F_1_ Male Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Postnatal Day^a^ | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Body Weight (g)^b,c^
28 | 82.0 ± 1.5** 72 (21) | 78.8 ± 1.2 84 (24) | 76.3 ± 0.9* 69 (19) | 71.9 ± 1.5** 74 (22)
91 | 396.6 ± 6.6** 67 (21) | 392.0 ± 4.2 79 (24) | 387.1 ± 3.9 64 (19) | 376.3 ± 4.0** 69 (22)
105 | 418.3 ± 6.9** 67 (21) | 411.5 ± 4.2 79 (24) | 408.4 ± 4.0 64 (19) | 396.4 ± 4.4** 69 (22)
Body Weight Gain (g)^b,c^
28–105 | 336.4 ± 5.6* 67 (21) | 332.6 ± 4.0 79 (24) | 332.3 ± 3.5 64 (19) | 324.5 ± 3.7 69 (22)
Postweaning Feed Consumption^d,e^
28–91 (g/animal/day) | 21.4 ± 0.3* (30) | 21.4 ± 0.2 (35) | 21.2 ± 0.3 (31) | 20.7 ± 0.3 (32)
28–91 (g/kg/day) | 79.1 ± 0.7** (30) | 79.9 ± 0.7 (35) | 80.8 ± 0.8 (31) | 81.9 ± 0.9** (32)
Chemical Intake (mg/kg/day)^f,g^
28–91 | 0.0 ± 0.0 (30) | 79.9 ± 0.7 (35) | 242.3 ± 2.3 (31) | 491.4 ± 5.3 (32)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n).

^b^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple comparisons.

^c^ n = number of pups examined (number of litters).

^d^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ n = number of cages.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

Figure 15

Postweaning Growth Curves for All F_1_ Male Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Information for statistical significance in F_1_ male rat weights is provided in Table 15.

Feed consumption (g/animal/day) over the entire postweaning period was not affected by EHMC exposure (Table 15). Significant decreases in absolute feed consumption were observed in the 6,000 ppm group after PND 70 (Appendix E). Relative feed consumption (g/kg/day) over the entire postweaning period were significantly increased in the 6,000 ppm group relative to the control group. Through PND 63, relative feed consumption was significantly increased due to the lower body weights of the animals (Appendix E). EHMC intake for F_1_ males, based on feed consumption and dietary concentrations for PND 28 through PND 91, was approximately 80, 242, and 491 mg/kg/day at 1,000, 3,000, and 6,000 ppm EHMC, respectively (Table 15).

##### Females (Postweaning)

Throughout the postweaning exposure period, mean body weights of females exposed to 6,000 ppm EHMC were significantly decreased (7%–14%) relative to the control group (Table 16; Figure 16); by PND 91, female mean body weights of the 6,000 ppm group were significantly decreased by 7% relative to the control group, suggesting a compensatory response. Female mean body weights of the 3,000 ppm group were significantly decreased (6%–11%) relative to the control group until PND 56, after which the mean body weights were <5% lower than the control group (Appendix E), suggesting a compensatory response. The mean body weights of females in the 1,000 ppm group were similar to those of the control group. Mean body weight gains of all groups of exposed females during the PND 28–91 interval were similar to those of the control group (Table 16).

Table 16 Summary of Postweaning Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of All F_1_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Postnatal Day^a^ | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Body Weight (g)^b,c^
28 | 75.4 ± 1.8** 80 (20) | 70.8 ± 1.1 94 (24) | 67.4 ± 1.0** 79 (19) | 64.5 ± 1.5** 85 (22)
91 | 253.0 ± 4.2** 67 (20) | 244.5 ± 3.7 79 (24) | 241.3 ± 3.0 64 (19) | 236.4 ± 2.9** 69 (22)
Body Weight Gain (g)^b,c^
28–91 | 177.4 ± 3.4 67 (20) | 173.7 ± 2.9 79 (24) | 174.2 ± 2.6 64 (19) | 171.8 ± 3.1 69 (22)
Postweaning Feed Consumption^d,e^
28–91 (g/animal/day) | 15.5 ± 0.2* (31) | 15.6 ± 0.2 (36) | 15.3 ± 0.2 (31) | 14.9 ± 0.1 (31)
28–91 (g/kg/day) | 84.5 ± 0.7* (31) | 87.0 ± 0.9 (36) | 87.5 ± 0.9* (31) | 88.0 ± 1.2* (31)
Chemical Intake (mg/kg/day)^f,g^
28–91 | 0.0 ± 0.0 (31) | 87.0 ± 0.9 (36) | 262.6 ± 2.7 (31) | 528.1 ± 7.0 (31)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n).

^b^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple comparisons.

^c^ n = number of pups examined (number of litters).

^d^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ n = number of cages.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

Figure 16

Postweaning Growth Curves for All F_1_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Information for statistical significance in F_1_ female rat weights is provided in Table 16.

In general, EHMC-exposed female rats displayed similar feed consumption values compared to the control group over the postweaning period (Table 16; Appendix E). In the 6,000 ppm group, absolute feed consumption significantly decreased during the PND 28–35 and PND 70–77 intervals, but there was no significant difference compared to the control group in the overall absolute feed consumption (g/animal/day) during the postweaning period (PND 28–91). Relative feed consumption (g/kg/day) significantly increased relative to the control group during some intervals by all of the exposed groups of females (Table 16; Appendix E). EHMC intake for F_1_ females, based on feed consumption and dietary concentrations for PND 28 through PND 91, was approximately 87, 263, and 528 mg/kg/day at 1,000, 3,000, and 6,000 ppm EHMC, respectively (Table 16).

### Developmental Endpoints

#### Anogenital Distance

F_1_ male, F_2_ male, and F_1_ female offspring exposed to EHMC did not display any alterations in PND 1 mean body weight-adjusted anogenital distance (AGD) (Table 17). F_2_ female offspring exposed to 6,000 ppm displayed a slightly shorter (6%) adjusted AGD compared to the F_2_ control group; however, this finding was likely the result of the F_2_ control group displaying slightly larger AGD than expected. All other AGDs across exposure groups and generations were similar to each other. Given this minimal magnitude, direction of change, and absence of pairwise statistical significance, this finding was not considered related to EHMC exposure.

Table 17 Summary of Anogenital Distance of F_1_ and F_2_ Male and Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Parameter^a^ | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Anogenital Distance (PND 1)
Male F_1_
No. examined^b^ | 131 (22) | 153 (24) | 110 (19) | 120 (22)
Adjusted AGD (mm)^c,d^ | 2.17 ± 0.03 | 2.19 ± 0.02 | 2.23 ± 0.03 | 2.19 ± 0.02
Male F_2_
No. examined | 165 (25) | 208 (33) | 167 (24) | 159 (25)
Adjusted AGD (mm) | 2.34 ± 0.05 | 2.31 ± 0.04 | 2.31 ± 0.07 | 2.23 ± 0.05
Female F_1_
No. examined | 104 (21) | 158 (24) | 111 (19) | 124 (22)
Adjusted AGD (mm) | 1.08 ± 0.03 | 1.07 ± 0.02 | 1.11 ± 0.03 | 1.12 ± 0.02
Female F_2_
No. examined | 194 (26) | 214 (33) | 185 (24) | 171 (25)
Adjusted AGD (mm) | 1.18 ± 0.03* | 1.17 ± 0.02 | 1.13 ± 0.03 | 1.11 ± 0.02

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

PND = postnatal day; AGD = anogenital distance.

^a^ Data are displayed as mean ± standard error. Animals found dead, cannibalized, or missing (presumed dead) were excluded from analysis. For F_1_ and F_2_ pups, data are displayed as the mean of litter values ± standard error of litter values (n = number of litters produced by F_0_ dams). For F_2_ pups, n is dependent on the number of litters produced by the F_0_ generation where up to two nonindependent F_1_ offspring/sex/litter were selected to produce F_2_ pups through nonsibling mating.

^b^ No. examined = number of pups examined (number of litters represented).

^c^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^d^ Adjusted AGD calculated using the formula: adjusted AGD = raw AGD – (slope*[body weight for that animal – overall body weight mean]), where the slope is the regression slope of AGD versus body weight.

#### Areolae/Nipple Retention

F_1_ male offspring exposed to EHMC exhibited occurrences (one pup each in the 1,000, 3,000, and 6,000 ppm groups) of areolae/nipple retention, which was not observed in the F_2_ male offspring (Appendix E).

#### Testicular Descent

Exposure to EHMC did not affect testicular descent in F_1_ or F_2_ male offspring (Appendix E).

#### Vaginal Opening

Females exposed to 3,000 or 6,000 ppm exhibited significant delays in the mean day of attaining vaginal opening (VO) (approximately 1.5 and 2.5 days, respectively) (Table 18). Mean body weights on day of attainment of the EHMC-exposed groups were similar to those of the control group. When weaning body weight was used to adjust day of VO attainment, the delays remained significant (Table 18). The adjusted individual and litter cumulative response graphs display an apparent shift to the right as a function of increasing exposure concentration (Figure 17; Appendix E).

Table 18 Summary of Vaginal Opening of F_1_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Parameter^a^ | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
No. Examined^b^ | 80 (20) | 94 (24) | 79 (19) | 84 (22)
No. Not Attaining^c^ | 0 | 0 | 0 | 0
Day of VO
Litter mean^d,e^ | 34.1 ± 0.3** | 35 ± 0.2 | 35.8 ± 0.4** | 36.8 ± 0.3**
Adjusted litter mean^d,e,f^ | 34.4 ± 0.3** | 35.1 ± 0.2 | 35.7 ± 0.3* | 36.5 ± 0.3**
Mean Body Weight at Acquisition (g)^g^ | 106.7 ± 2.0 | 107.3 ± 1.3 | 107.1 ± 1.4 | 107.7 ± 2.4
Mean Body Weight at Weaning (g)^g^ | 77.5 ± 1.8** | 73.0 ± 1.1 | 69.4 ± 1.0** | 66.1 ± 1.6**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

VO = vaginal opening.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ No. Examined = the number of pups examined (number of litters).

^c^ No. Not Attaining = number of pups that survived to the end of the observation period without attaining VO.

^d^ Summary statistics and mixed model results are presented for animals that attained during the observation period.

^e^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^f^ Adjusted based on body weight at weaning.

^g^ Analysis of body weight at acquisition and body weight at weaning for both linear trend and pairwise comparisons performed using mixed effects models with litter as a random effect and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

Figure 17

Time to Vaginal Opening of F_1_ Female Offspring Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Cumulative response curves are shown for (A) litter response and (B) litter response adjusted for body weight at weaning.

#### Balanopreputial Separation

Male rats in the 6,000 ppm group displayed a significant delay (approximately 3.5 days) in the mean day of attaining balanopreputial separation (BPS) when analyzed as litter means (Table 19). When graphically expressed as a cumulative litter response the 6,000 ppm group shifted to the right (Figure 18; Appendix E). Mean body weights on day of attainment were similar, and when litter means were adjusted using the corresponding body weight on day of weaning, this delay was slightly shortened—but remained significant—relative to the control group (Table 19; Figure 18). The cumulative litter mean and individual PND 28-adjusted responses for the 6,000 ppm group still display the shift to the right (Figure 18; Appendix E).

Table 19 Summary of Balanopreputial Separation of F_1_ Male Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Parameter^a^ | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
No. Examined^b^ | 72 (21) | 84 (24) | 69 (19) | 74 (22)
No. Not Attaining^c^ | 0 | 0 | 0 | 0
Day of BPS
Litter mean^d,e^ | 44.9 ± 0.3** | 45.4 ± 0.6 | 45.3 ± 0.4 | 48.4 ± 0.6**
Adjusted litter mean^d,e,f^ | 45.6 ± 0.3** | 45.6 ± 0.6 | 45.2 ± 0.3 | 47.8 ± 0.5**
Mean Body Weight at Acquisition (g)^g^ | 207.9 ± 3.5 | 203.5 ± 4.0 | 199.2 ± 1.9 | 214.1 ± 3.4
Mean Body Weight at Weaning (g)^g^ | 84.5 ± 1.6** | 80.9 ± 1.2 | 78.2 ± 0.9** | 73.6 ± 1.5**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BPS = balanopreputial separation.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ No. Examined = number of pups examined (number of litters).

^c^ No. Not Attaining = number of pups that survived to the end of the observation period without attaining BPS.

^d^ Summary statistics and mixed model results are presented for animals that attained during the observation period.

^e^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^f^ Adjusted based on body weight at weaning.

^g^ Analysis of body weight at acquisition and body weight at weaning for both linear trend and pairwise comparisons performed using mixed effects models with litter as a random effect and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

Figure 18

Time to Balanopreputial Separation of F_1_ Male Offspring Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Cumulative response curves are shown for (A) litter response and (B) litter response adjusted for body weight at weaning.

## F_1_ Cohort Data

### Prenatal and Reproductive Performance Cohorts: Mating and Fertility

F_1_ male and female rats from the prenatal and reproductive performance cohorts were mated and evaluated for reproductive endpoints, as shown in Figure 19. Viability, clinical observations, vaginal cytology, fertility, andrology, mean body weights, and feed consumption results are presented below.

Figure 19

Design of the Modified One-Generation Study–Prenatal and Reproductive Performance Cohorts

GD = gestation day; LD = lactation day; PND = postnatal day.

#### Viability and Clinical Observations

There were no EHMC-related clinical observations, and no morbidity or mortality, in the prenatal and reproductive performance cohorts (Appendix E).

#### Selection and Mating

A male and a female, or two males and two females (1:1), from each litter were allocated to the prenatal and reproductive performance cohorts, respectively; avoiding sibling mating (Figure 19). Vaginal lavage samples were collected for approximately 2 weeks prior to cohabitation and continued until evidence of mating or until the cohabitation period was completed.

#### Vaginal Cytology

The collective analysis of F_1_ female vaginal cytology indicated that EHMC exposure did not affect the number of rats that were cycling or overall cycle length (Table 20; Figure 20). However, rats in the 6,000 ppm group spent more time in estrus compared to the control group (approximately 28% of the days versus approximately 20%, respectively). Analysis of estrous cyclicity utilizing the continuous-time Markov model demonstrated a slight but significant increase in estrus stage length in all EHMC-exposed groups compared to the control (Table 20; Figure 20; Appendix E).

Table 20 Markov Model Estimates of Estrous Stage Length and 95% Confidence Intervals for All F_1_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Stage^a^ | 0 ppm | | 1,000 ppm | | 3,000 ppm | | 6,000 ppm
Stage^a^ | Stage Length (Days) | 95% CI | Stage Length (Days) | 95% CI | Stage Length (Days) | 95% CI | Stage Length (Days) | 95% CI
Diestrus | 3.7 | (3.3, 4.3) | 3.0* | (2.7, 3.3) | 3.3 | (2.9, 3.8) | 2.9** | (2.5, 3.2)
Proestrus | 0.4 | (0.3, 0.4) | 0.4 | (0.4, 0.5) | 0.3 | (0.2, 0.4) | 0.3 | (0.2, 0.4)
Estrus | 1.1 | (1.0, 1.2) | 1.3** | (1.2, 1.4) | 1.3** | (1.2, 1.4) | 1.3** | (1.2, 1.4)
Metestrus | 0.2 | –^b^ | 0.2 | – | 0.2 | – | 0.2 | –

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p < 0.05; **p < 0.01.

CI = confidence interval.

^a^ Pairwise tests are performed using a permutation null hypothesis testing method and have been adjusted for multiple comparisons using a Hommel correction within each stage.

^b^ Due to a very low number of observations of metestrus, stage lengths were estimated using a profile likelihood approach. As a result, confidence intervals are not available for the metestrus stage length estimate.

Figure 20

Markov Model Estimates of Estrous Stage Length and 95% Confidence Intervals for All F_1_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Dots = estimated stage lengths; bars = 95% confidence intervals; low = 1,000 ppm; mid = 3,000 ppm; high = 6,000 ppm.

Metestrus estimates are not shown here due to very low numbers of observations of this stage. Y-axis scales differ for each stage.

#### Fertility

The precoital interval and number of females that mated (i.e., those that were sperm-positive, littered, or had implantation sites) were similar across the EHMC-exposed groups and the control group (Table 21). The number of pregnant females was also similar among groups, indicating that F_1_ male and female fertility was not affected by EHMC exposure at the concentrations examined. Responses observed were consistent between the cohorts.

Table 21 Summary of Mating and Fertility Performance of F_1_ Male and Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Parameter^a^ | 0 ppm | | 1,000 ppm | | 3,000 ppm | | 6,000 ppm
Parameter^a^ | RPC | PC | RPC | PC | RPC | PC | RPC | PC
No. Mating Pairs | 36 | 21 | 46 | 23 | 35 | 19 | 37 | 22
No. Mated | 34 | 19 | 41 | 21 | 32 | 18 | 34 | 20
No. Females Pregnant | 27 | 19 | 35 | 18 | 27 | 15 | 27 | 16
Percent of Mated Females/Paired^b^ | 94.4 | 90.5 | 89.1 | 91.3 | 91.4 | 94.7 | 91.9 | 90.9
Precoital Interval^c,d^ | 4.9 ± 0.7 (19) | 4.3 ± 0.9 (19) | 5.1 ± 0.6 (22) | 4.9 ± 1.0 (21) | 4.8 ± 0.7 (19) | 2.9 ± 0.6 (15) | 4.6 ± 0.6 (20) | 5.4 ± 0.9 (20)

RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Statistical analysis of the RPC performed using the Rao-Scott Cochran-Armitage test for both trend and pairwise comparisons to adjust for litter effects. Statistical analysis of the PC performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^c^ Statistical analysis of the RPC performed using a bootstrapped Jonckheere test for trend, and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons. Statistical analysis for the PC cohort performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ Precoital interval in days is calculated for sperm-positive females; data are displayed as mean ± standard error (n).

#### F_1_ Reproductive Performance Cohort Andrology

There were no EHMC-related effects on motile sperm, progressively motile sperm, testis spermatid head, cauda epididymal sperm counts, or cauda epididymal sperm concentration in the reproductive performance cohort (Appendix E). Males in the 6,000 ppm group displayed slightly higher cauda epididymis weights (6%, positive trend), but epididymis and testis weights were similar to those of the control group. These findings were not associated with histopathological changes or significant changes in reproductive performance (Appendix E).

#### Gestation Body Weights

As previously reported, in the F_1_ Body Weights and Feed Consumption section, females in the 3,000 ppm group had significantly decreased mean body weights at postweaning (PND 28), but their body weights recovered by sexual maturity (PND 91) and were similar to those of the control group (Table 16). In contrast, at sexual maturity before mating (PND 91), mean body weights of females in the 6,000 ppm group were significantly decreased by approximately 7% relative to the control group (Table 16). GD 0 mean body weights of the reproductive performance cohort were also slightly lower (5%, negative trend) (Table 22). This response on GD 0 was not observed in the prenatal cohort, likely due to the smaller number of animals and litters represented. Females in the 6,000 ppm group in the reproductive performance cohort displayed slightly lower (approximately 5%) gestation mean body weights than the control group, often attaining statistical significance (Appendix E). Collectively, these findings suggest the EHMC-related responses observed on gestation mean body weight were consistent between the cohorts; nonetheless, the apparent magnitude of this response is small. Gestational body weight curves of the exposed groups in both cohorts generally paralleled those of the control groups (Figure 21, Figure 22). In both cohorts, GD 0–21 mean body weight gains of the EHMC-exposed groups were similar those of the control groups (Table 22).

Table 22 Summary of Gestation Mean Body Weight Gains for F_1_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed^a,b,c^

GD Interval | 0 ppm | | 1,000 ppm | | 3,000 ppm | | 6,000 ppm
GD Interval | RPC | PC | RPC | PC | RPC | PC | RPC | PC
n^d^ | 16 | 19 | 22 | 18 | 19 | 12 | 18 | 16
0 | 260.5 ± 5.7* | 247.8 ± 6.4 | 258.9 ± 4.4 | 248.1 ± 4.8 | 253.9 ± 4.6 | 238.3 ± 4.1 | 246.5 ± 2.8 | 246.5 ± 3.3
0–21 | 170.5 ± 6.2 | 168.0 ± 3.5 | 157.6 ± 5.1 | 147.8 ± 8.4* | 165.3 ± 6.5 | 170.9 ± 3.0 | 155.7 ± 5.8 | 151.9 ± 5.5
0–3 | 18.3 ± 1.6 | 16.1 ± 1.2 | 16.3 ± 1.0 | 14.4 ± 0.8 | 16.5 ± 1.0 | 18.5 ± 1.3 | 17.5 ± 0.7 | 14.1 ± 0.8
3–6 | 11.9 ± 1.0 | 10.8 ± 0.8 | 11.2 ± 0.7 | 11.3 ± 0.8 | 12.1 ± 0.8 | 12.5 ± 0.8 | 10.8 ± 0.5 | 10.8 ± 0.7
6–9 | 12.5 ± 0.9 | 12.2 ± 0.6 | 11.8 ± 0.8 | 11.3 ± 0.6 | 11.5 ± 0.9 | 12.5 ± 0.7 | 11.1 ± 0.9 | 10.9 ± 0.7
9–12 | 14.9 ± 1.0 | 14.2 ± 0.6 | 14.1 ± 0.8 | 13.4 ± 1.0 | 14.7 ± 0.9 | 14.8 ± 1.0 | 14.8 ± 1.0 | 11.5 ± 0.9
12–15 | 19.7 ± 1.3 | 21.5 ± 0.8 | 17.2 ± 0.9 | 17.3 ± 1.4* | 20.2 ± 1.1 | 21.6 ± 0.8 | 16.9 ± 1.0 | 21.4 ± 1.1
15–18 | 45.2 ± 1.9 | 47.0 ± 1.7* | 42.3 ± 2.1 | 39.0 ± 3.2* | 42.8 ± 2.6 | 45.0 ± 1.7 | 41.3 ± 2.2 | 39.9 ± 2.0
18–21 | 48.1 ± 2.2 | 46.1 ± 1.7 | 44.7 ± 1.8 | 41.1 ± 3.0 | 47.6 ± 2.4 | 46.0 ± 1.3 | 43.3 ± 2.1 | 43.2 ± 2.1

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

GD = gestation day; RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Data are displayed as mean ± standard error. Body weight data are reported in grams.

^c^ Statistical analysis for the RPC performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons. Statistical analysis for the PC performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ n = number of litters.

Figure 21

Gestation Growth Curves for F_1_ Female Rats in the Reproductive Performance Cohort Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Information for statistical significance in F_1_ female rat weights is provided in Appendix E.

Figure 22

Gestation Growth Curves for F_1_ Female Rats in the Prenatal Cohort Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Information for statistical significance in F_1_ female rat weights is provided in Appendix E.

#### Gestation Feed Consumption

Gestational feed consumption (g/animal/day) was significantly decreased in the 6,000 ppm group of the reproductive performance cohort with a negative trend in the prenatal cohort during the GD 0–21 interval. When expressed as a function of body weight (g/kg/day), however, it was similar to that of the control groups (Table 23; Appendix E).

Table 23 Summary of Gestation Feed and Test Article Consumption for F_1_ Female Rats Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed^a,b,c^

GD Interval | 0 ppm | | 1,000 ppm | | 3,000 ppm | | 6,000 ppm
GD Interval | RPC | PC | RPC | PC | RPC | PC | RPC | PC
Feed Consumption (g/animal/day)^d^
0–21 | 24.0 ± 0.6 (16) | 22.9 ± 0.5* (19) | 23.1 ± 0.4 (22) | 22.5 ± 0.5 (18) | 23.0 ± 0.3 (19) | 22.2 ± 0.6 (12) | 22.1 ± 0.4* (18) | 21.6 ± 0.3 (16)
0–3 | 21.4 ± 0.6 (16) | 19.9 ± 0.8* (19) | 20.3 ± 0.5 (21) | 20.4 ± 0.6 (18) | 20.6 ± 0.5 (19) | 19.3 ± 0.6 (12) | 19.8 ± 0.3 (18) | 18.5 ± 0.3 (16)
3–6 | 21.8 ± 0.6 (16) | 21.0 ± 0.8 (18)^e^ | 21.3 ± 0.4 (22) | 20.7 ± 0.4 (18) | 21.8 ± 0.2 (19) | 20.2 ± 0.4 (12) | 20.4 ± 0.3 (18) | 20.0 ± 0.2 (16)
6–9 | 23.9 ± 0.9* (16) | 22.4 ± 0.8* (19) | 22.6 ± 0.5 (22) | 22.1 ± 0.7 (17)^e^ | 22.1 ± 0.4 (19) | 21.6 ± 0.7 (12) | 21.2 ± 0.4* (18) | 20.6 ± 0.3 (16)
9–12 | 22.7 ± 0.5 (16) | 21.2 ± 0.5 (19) | 22.0 ± 0.4 (22) | 21.9 ± 0.6 (18) | 22.2 ± 0.2 (19) | 20.8 ± 0.5 (12) | 21.1 ± 0.4 (18) | 20.4 ± 0.3 (16)
12–15 | 24.2 ± 0.7 (16) | 23.7 ± 0.6 (19) | 23.0 ± 0.4 (22) | 22.7 ± 0.6 (18) | 22.9 ± 0.4 (19) | 22.3 ± 0.8 (12) | 22.1 ± 0.6 (18) | 22.3 ± 0.4 (16)
15–18 | 26.3 ± 0.7 (16) | 25.7 ± 0.4 (19) | 25.3 ± 0.4 (22) | 24.0 ± 0.5** (18) | 25 ± 0.4 (19) | 25.1 ± 0.6 (12) | 24.4 ± 0.5 (18) | 24.3 ± 0.4 (16)
18–21 | 27.7 ± 0.6 (16) | 26.7 ± 0.8 (19) | 27.0 ± 0.7 (22) | 25.3 ± 0.6 (18) | 26.9 ± 0.5 (19) | 25.9 ± 1.2 (12) | 25.6 ± 0.8 (18) | 24.8 ± 0.6 (16)
Feed Consumption (g/kg/day)^d^
0–21 | 74.2 ± 1.1 (16) | 74.8 ± 2.0 (19) | 73.2 ± 1.2 (22) | 74.4 ± 1.3 (18) | 73.5 ± 0.8 (19) | 73.3 ± 1.3 (12) | 72.5 ± 0.9 (18) | 71.7 ± 0.9 (16)
0–3 | 79.2 ± 2.1 (16) | 78.3 ± 3.7 (19) | 76.1 ± 1.8 (21) | 80.3 ± 2.3 (18) | 78.4 ± 1.4 (19) | 77.7 ± 1.7 (12) | 77.4 ± 1.0 (18) | 72.8 ± 1.1 (16)
3–6 | 76.8 ± 1.8 (16) | 77.9 ± 3.7 (18) | 76.0 ± 1.3 (22) | 77.3 ± 1.3 (18) | 78.8 ± 0.8 (19) | 76.7 ± 1.5 (12) | 75.5 ± 1.0 (18) | 75.1 ± 1.1 (16)
6–9 | 80.4 ± 2.2 (16) | 80.2 ± 3.5 (19) | 77.7 ± 1.6 (22) | 79.2 ± 2.2 (17) | 77.0 ± 1.2 (19) | 78.2 ± 1.8 (12) | 75.6 ± 1.3 (18) | 74.6 ± 1.3 (16)
9–12 | 73.0 ± 1.0 (16) | 72.2 ± 1.4 (19) | 72.3 ± 1.2 (22) | 74.9 ± 1.7 (18) | 73.7 ± 1.0 (19) | 72.0 ± 1.4 (12) | 72.0 ± 1.1 (18) | 70.9 ± 1.1 (16)
12–15 | 73.9 ± 1.4 (16) | 76.4 ± 2.1 (19) | 72.0 ± 1.2 (22) | 74.4 ± 2.1 (18) | 72.1 ± 1.1 (19) | 72.8 ± 2.0 (12) | 71.5 ± 1.5 (18) | 73.7 ± 1.4 (16)
15–18 | 73.4 ± 0.9 (16) | 74.7 ± 1.0 (19) | 72.5 ± 1.3 (22) | 71.8 ± 1.1 (18) | 71.7 ± 1.1 (19) | 74.0 ± 1.0 (12) | 72.4 ± 0.8 (18) | 72.9 ± 1.1 (16)
18–21 | 68.1 ± 1.7 (16) | 68.0 ± 2.0 (19) | 68.5 ± 1.8 (22) | 67.6 ± 1.5 (18) | 68.0 ± 1.3 (19) | 66.9 ± 2.8 (12) | 67.4 ± 2.0 (18) | 65.9 ± 1.5 (16)
Chemical Intake (mg/kg/day)^f,g^
0–21 | 0.0 ± 0.0 (16) | 0.0 ± 0.0 (19) | 73.2 ± 1.2 (22) | 74.4 ± 1.3 (18) | 220.5 ± 2.5 (19) | 220.0 ± 3.9 (12) | 435.1 ± 5.7 (18) | 430.3 ± 5.4 (16)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

Consumption is only reported for pregnant animals.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Data are displayed as mean ± standard error (n), where n = number of litters.

^c^ For each dam, calculation of consumption values for the GD 0–21 interval was performed using all valid data for the animal, even if data were unavailable for some of the subintervals.

^d^ Statistical analysis of the RPC performed using a bootstrapped Jonckheere test for trend and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons. Statistical analysis of the PC performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Excludes feed consumption from cages where excess food spillage was observed.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

### Prenatal Cohort Findings

F_1_ rats and F_2_ fetuses from the prenatal cohort were evaluated for maternal reproductive performance and fetal findings, respectively, as shown in Figure 23.

Figure 23

Design of the Modified One-Generation Study–Prenatal Cohort

GD = gestation day; LD = lactation day; PND = postnatal day.

#### Maternal Reproductive Performance and Uterine Data

In the prenatal cohort, females were between 111 and 113 days of age at the time of laparotomy. There was no effect of EHMC exposure on the number of implants, postimplantation loss, number of live fetuses, sex ratio, fetal weight, or gravid uterine weight (Table 24). Terminal and adjusted terminal mean body weights of the EHMC-exposed groups were similar to the control group.

Table 24 Summary of Uterine Content Data for F_1_ Female Rats in the Prenatal Cohort Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

| 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Pregnancy Summary^a^
Paired Females | 21 | 23 | 19 | 22
Mated Females | 19 | 21 | 18 | 20
Pregnant Females^b^ | 19 | 18 | 15 | 16
Pregnant Females Examined on GD 21 | 19 | 18 | 12 | 16
Preimplantation Loss^c,d^
Mean No. of Corpora Lutea/Female | 17.74 ± 0.73 (19) | 16.22 ± 0.55 (18) | 18.71 ± 0.61 (14) | 17.50 ± 0.74 (16)
Implantations/Female | 15.21 ± 0.68 (19) | 13.11 ± 1.19 (18) | 15.75 ± 0.51 (12) | 14.19 ± 0.88 (16)
Preimplantation Loss (%) | 13.60 ± 3.52 (19) | 21.73 ± 6.42 (18) | 14.11 ± 2.65 (12) | 18.54 ± 4.59 (16)
Intrauterine Deaths^d^
Postimplantation Loss (%)^c^ | 1.89 ± 0.80 (19) | 10.00 ± 6.24 (18) | 3.21 ± 1.28 (12) | 4.78 ± 1.48 (16)
Total Resorptions per Litter^c^ | 0.32 ± 0.13 (19) | 0.39 ± 0.18 (18) | 0.42 ± 0.19 (12) | 0.56 ± 0.16 (16)
Early Resorptions per Litter^c^ | 0.32 ± 0.13 (19) | 0.33 ± 0.18 (18) | 0.42 ± 0.19 (12) | 0.56 ± 0.16 (16)
Late Resorptions per Litter^c^ | 0.00 ± 0.00 (19) | 0.06 ± 0.06 (18) | 0.00 ± 0.00 (12) | 0.00 ± 0.00 (16)
Dead Fetuses per Litter^c^ | 0.00 ± 0.00 (19) | 0.00 ± 0.00 (18) | 0.08 ± 0.08 (12) | 0.00 ± 0.00 (16)
No. of Early Resorptions | 6 | 6 | 5 | 9
No. of Late Resorptions | 0 | 1 | 0 | 0
No. of Whole Litter Resorptions^a^ | 0 | 1 | 0 | 0
No. of Dead Fetuses | 0 | 0 | 1 | 0
Live Fetuses^d^
No. of Live Fetuses (Litters) | 283 (19) | 229 (17) | 183 (12) | 218 (16)
Live Fetuses per Litter^e^ | 14.89 ± 0.65 | 13.47 ± 1.11 | 15.25 ± 0.54 | 13.63 ± 0.93
Live Male Fetuses per Litter^e^ | 7.63 ± 0.49 | 6.47 ± 0.59 | 6.75 ± 0.57 | 7.13 ± 0.53
Live Female Fetuses per Litter^e^ | 7.26 ± 0.55 | 7.00 ± 0.66 | 8.50 ± 0.51 | 6.50 ± 0.58
Live Male Fetuses per Litter (%)^e^ | 51.75 ± 2.73 | 48.57 ± 2.11 | 44.06 ± 3.30 | 53.49 ± 2.62
Fetal Weight (g)^e,f^
Fetal Weight per Litter | 5.10 ± 0.08 | 5.07 ± 0.09 | 4.97 ± 0.06 | 4.97 ± 0.08
Male Fetal Weight per Litter | 5.26 ± 0.08 | 5.19 ± 0.10 | 5.07 ± 0.08 | 5.12 ± 0.09
Female Fetal Weight per Litter | 4.94 ± 0.08 | 4.97 ± 0.08 | 4.88 ± 0.05 | 4.80 ± 0.08
Gravid Uterine Weight (g)^e,f^
Gravid Uterine Weight | 105.57 ± 3.94 | 90.37 ± 8.39^h^ | 105.90 ± 3.18 | 95.98 ± 5.59
Terminal Body Weight | 414.4 ± 7.8 | 397.6 ± 9.9^h^ | 410.4 ± 6.0 | 397.9 ± 7.3
Adjusted Body Weight^g^ | 308.85 ± 6.13 | 307.22 ± 5.12^h^ | 304.54 ± 4.79 | 301.96 ± 4.60

GD = gestation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Number pregnant included animals that had evidence of pregnancy but were removed from the study before GD 21.

^c^ Data are reported per litter as mean ± standard error (number of females) and do not include nonmated, nonpregnant, or unexamined animals or those that did not survive to the end of the study.

^d^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Data are reported per litter as mean ± standard error and do not include nonpregnant animals or those that did not survive to the end of the study.

^f^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^g^ Body weight adjusted for gravid uterus weight.

^h^ Sample size of n = 18.

#### Fetal Findings

##### Placental Morphology

There was no effect of EHMC exposure on the incidence of placental abnormalities in the prenatal cohort (Appendix E). Fused placentae between two adjacent fetuses were noted for a single litter in the 1,000 ppm group.

##### External

There was no effect of EHMC exposure on the incidence of fetal external abnormalities in the prenatal cohort (Appendix E). Fetal external abnormalities were limited to a single fetus in the 6,000 ppm group with a right clubbed hindlimb and a single incidence of left clubbed hindlimb in the control group.

##### Visceral

There was no effect of EHMC exposure on the incidence of fetal visceral abnormalities in the prenatal cohort (Appendix E). Male and female fetuses (combined) exposed to 6,000 ppm displayed a higher incidence of hydronephrosis (malformation; four in one litter) with a positive trend. One animal in the control group had unilateral (right) hydronephrosis, as did one fetus in the 3,000 ppm group. The incidences of dilated renal pelvis (variation), distended ureter (variation), and hydroureter (malformation) in the EHMC-exposed groups were similar to those in the control groups (Appendix E). When the kidney and ureter malformations were combined, no EHMC-related differences in individual and litter incidences were observed. Similarly, EHMC exposure was not associated with a higher incidence of combined dilated renal pelvis or distended ureter variations (Appendix E).

##### Head

There was no effect of EHMC exposure on the incidence of fetal head abnormalities in the prenatal cohort (Appendix E).

##### Skeletal

There was no effect of EHMC exposure on the incidence of fetal skeletal malformations in the prenatal cohort (Appendix E).

Fetuses exposed to 6,000 ppm displayed a slightly higher individual (positive trend) and litter incidence of the variation of left, lumbar 1 rudimentary rib compared with the control group (Table 25). The incidence of bilateral lumbar 1 rudimentary rib in the 6,000 ppm group was slightly higher than the control group. When all lumbar 1 rudimentary rib variants were combined, the combined fetal incidence of rudimentary lumbar 1 ribs was higher in the 6,000 ppm group than in the control group (10% versus 4%, respectively) (Table 25).

Table 25 Summary of Select Skeletal Findings in Fetuses Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

| 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
No. Litters Examined | 19 | 17 | 12 | 16
No. Fetuses Examined | 283 | 211 | 183 | 218
Ribs^a,b^
Lumbar, 1, Unilateral or Bilateral, Rudimentary – [V]^c^
Fetuses | 12 (4.24) | 8 (3.79) | 7 (3.83) | 22 (10.09)
Litters | 5 (26.32) | 5 (29.41) | 2 (16.67) | 7 (43.75)
Lumbar, 1, Bilateral, Rudimentary – [V]^d^
Fetuses | 4 (1.41) | 4 (1.90) | 4 (2.19) | 8 (3.67)
Litters | 2 (10.53) | 3 (17.65) | 2 (16.67) | 5 (31.25)
Lumbar, 1, Left, Rudimentary – [V]^e^
Fetuses | 0 (0.00)^#^ | 4 (1.90) | 0 (0.00) | 8 (3.67)
Litters | 0 (0.00) | 4 (23.53) | 0 (0.00) | 4 (25.00)
Lumbar, 1, Right, Rudimentary – [V]^f^
Fetuses | 8 (2.83) | 0 (0.00) | 3 (1.64) | 6 (2.75)
Litters | 5 (26.32) | 0 (0.00) | 1 (8.33) | 4 (25.00)

Statistical significance for the vehicle control group indicates a significant trend test.

^#^ Statistically significant at p ≤ 0.05 (litter-based analysis).

[V] = variation.

^a^ Upper row denotes number of affected fetuses (%) and lower row the number of affected litters (%).

^b^ Statistical analysis for fetal data including litter effects performed using a Rao-Scott modification to the Cochran-Armitage test in which the litter was the random effect for both trend and pairwise analyses.

^c^ Historical control incidence: fetuses – 82/1,385 (5.92%), range 0.00% to 13.69%; litters – 29/97 (29.90%), range 0.00% to 65.91%.

^d^ Historical control incidence: fetuses – 7/1,385 (0.51%), range 0.00% to 1.41%; litters – 4/97 (4.12%), range 0.00% to 12.50%.

^e^ Historical control incidence: fetuses – 5/1,385 (0.36%), range 0.00% to 2.14%; litters – 4/97 (4.12%), range 0.00% to 25.00%.

^f^ Historical control incidence: fetuses – 11/1,385 (0.79%), range 0.00% to 2.83%; litters – 8/97 (8.25%), range 0.00% to 26.32%.

### Reproductive Performance Cohort Findings

F_1_ and F_2_ rats from the reproductive performance cohort were evaluated for maternal reproductive performance and offspring effects, respectively, as shown in Figure 24. Littering, mean body weights, and feed consumption results from the F_1_ rats as well as viability, clinical observations, mean body weights, and gross pathology results from the F_2_ rats are presented below.

Figure 24

Design of the Modified One-Generation Study–Reproductive Performance Cohort

GD = gestation day; LD = lactation day; PND = postnatal day.

#### Reproductive Performance and Littering

In the reproductive performance cohort, the time to mating, number of females mated, pregnant, and littering were similar among the EHMC-exposed groups and similar to the control group (Table 26). Although gestation length was generally similar among the EHMC-exposed groups and the control group, gestational length appeared slightly, but significantly, decreased (approximately 7 hours) in the 3,000 ppm group. Given the low confidence in capturing the actual time that mating occurred (time is often recorded the morning when the presence of a vaginal copulation plug or sperm in a vaginal lavage is confirmed), the small magnitude of the response, and absence of an exposure concentration response, the shortened duration of gestation was not considered related to EHMC exposure.

Table 26 Summary of Reproductive Parameters of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

| 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
No. Females Paired | 36 | 46 | 35 | 37
No. Females Mated | 34 | 41 | 32 | 34
No. Females Littering | 26 | 34 | 24 | 26
Percent of Mated Females/Paired^a,b^ | 94.4 | 89.1 | 91.4 | 91.9
Percent of Littered Females/Paired^a,b^ | 72.2 | 73.9 | 70.6 | 70.3
Percent of Littered Females/Mated^a,b^ | 76.5 | 82.9 | 77.4 | 76.5
Precoital Interval (days)^c,d,e^ | 4.9 ± 0.7 (19) | 5.1 ± 0.6 (22) | 4.8 ± 0.7 (19) | 4.6 ± 0.6 (20)
Gestation Length (days)^c,d,f^ | 22.5 ± 0.1* (16) | 22.7 ± 0.1 (22) | 22.2 ± 0.1* (18) | 22.3 ± 0.1 (18)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Statistical analysis performed using the Rao-Scott Cochran-Armitage test for both trend and pairwise comparisons to adjust for litter effects (unless otherwise noted).

^b^ Animals removed from study between mating and littering were excluded from calculations of percent littered females.

^c^ Statistical analysis performed using a bootstrapped Jonckheere test for trend and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

^d^ Data are displayed as mean ± standard error (n).

^e^ Precoital interval calculated for sperm-positive females.

^f^ Gestation length calculated for sperm-positive females that delivered a litter.

#### Lactation Body Weights and Feed Consumption

Consistent with their premating and gestational body weights, F_1_ female mean body weights during lactation were significantly decreased in the 6,000 ppm group compared to the control group by 6% and 7% on LD 1 and LD 13, respectively (Table 27; Figure 25). On LD 28, female mean body weights of the 6,000 ppm group were 5% lower than those of the control group. Mean body weight gain between LD 1 and LD 28 of the 6,000 ppm group was higher than that of the control group. In general, feed consumption during lactation by the EHMC-exposed groups was similar to that by the control group (Table 27). EHMC intake during lactation, based on feed consumption and dietary concentrations for LD 1–13, was exposure concentration-proportional and approximately 139, 418, and 842 mg/kg/day at exposure concentrations of 1,000, 3,000, and 6,000 ppm, respectively (Table 27).

Table 27 Summary of Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed during Lactation

Lactation Day^a^ | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Body Weight (g)^b^
1 | 318.0 ± 6.2** (18) | 310.2 ± 3.9 (23) | 306.0 ± 4.5 (18) | 297.5 ± 4.0* (18)
13 | 340.2 ± 5.3** (18) | 334.5 ± 4.5 (22) | 323.8 ± 4.0 (16) | 316.4 ± 2.9** (17)
28 | 318.7 ± 5.8* (18) | 311.4 ± 4.5 (22) | 304.2 ± 5.3 (16) | 302.6 ± 3.4 (17)
Body Weight Gain (g)^b^
1–28 | 0.6 ± 3.2 (18) | 2.6 ± 3.0 (22) | 2.3 ± 3.1 (16) | 8.0 ± 3.2 (17)
Feed Consumption^c^
1–13 (g/animal/day) | 45.3 ± 1.7 (18) | 44.6 ± 1.2 (22) | 43.8 ± 2.0 (18) | 43.1 ± 1.4 (18)
1–13 (g/kg/day) | 137.9 ± 5.9 (18) | 138.5 ± 3.9 (22) | 139.2 ± 6.4 (18) | 140.4 ± 5.5 (18)
Chemical Intake (mg/kg/day)^d,e^
1–13 | 0 ± 0.0 (18) | 138.5 ± 3.9 (22) | 417.5 ± 19.2 (18) | 842.4 ± 32.8 (18)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error (n), where n = number of litters.

^b^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple comparisons.

^c^ Statistical analysis performed using a bootstrapped Jonckheere test for trend and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

^d^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^e^ No statistical analysis performed on the chemical intake data.

Figure 25

Lactation Growth Curves for F_1_ Female Rats in the Reproductive Performance Cohort Exposed to 2-Ethylhexyl p-Methoxycinnamate in Feed

Information for statistical significance in F_1_ female rat weights is provided in Table 27.

#### F_2_ Viability and Clinical Observations

Mean total and live litter size of the EHMC-exposed groups from the reproductive performance cohort were similar to the control group, and pup survival was unaffected by EHMC exposure (Table 28). Similar analogous litter parameters were observed in the prenatal cohort.

Table 28 Summary of F_2_ Litter Size and Pup Survival Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate

Postnatal Day | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
No. of Live Pups (Litters)^a^
0 | 396 (26) | 464 (34) | 382 (24) | 363 (26)
Total Litter Size^b,c^
0 | 15.3 ± 0.8 (18) | 13.6 ± 0.8 (23) | 16.1 ± 0.6 (18) | 13.7 ± 0.9 (18)
Live Litter Size^b,c^
0 | 14.1 ± 0.8 (18) | 13.0 ± 0.7 (23) | 15.0 ± 0.6 (18) | 13.1 ± 0.8 (18)
1 | 13.8 ± 1.0 (18) | 13.0 ± 0.7 (22) | 14.7 ± 0.6 (18) | 12.8 ± 0.8 (18)
4 (prestandardization) | 13.5 ± 0.9 (18) | 13.1 ± 0.7 (22) | 14.0 ± 0.8 (18) | 12.5 ± 0.8 (18)
4 (poststandardization) | 9.4 ± 0.5 (18) | 9.4 ± 0.3 (22) | 9.6 ± 0.4 (18) | 9.3 ± 0.4 (18)
7 | 8.7 ± 0.7 (18) | 8.8 ± 0.4 (22) | 9.3 ± 0.4 (16) | 8.9 ± 0.6 (18)
13 | 7.4 ± 0.7 (18) | 8.2 ± 0.5 (22) | 8.0 ± 0.6 (16) | 8.4 ± 0.6 (17)
21 | 7.4 ± 0.7 (18) | 8.2 ± 0.5 (22) | 8.0 ± 0.6 (16) | 8.4 ± 0.6 (17)
28 | 7.4 ± 0.7 (18) | 8.2 ± 0.5 (22) | 8.0 ± 0.6 (16) | 8.4 ± 0.6 (17)
No. of Dead Pups (Litters)^b,c^
0 | 30 (16) | 23 (15) | 23 (9) | 24 (17)
1–4 | 13 (7) | 26 (12) | 33 (9) | 18 (10)
5–28 | 44 (16) | 43 (10) | 52 (16) | 38 (11)
Dead per Litter^b,c^
0 | 1.21 ± 0.27 (18) | 0.59 ± 0.17 (23) | 1.06 ± 0.30 (18) | 1.00 ± 0.23 (18)
1–4 | 0.56 ± 0.22 (18) | 0.85 ± 0.37 (23) | 1.08 ± 0.66 (18) | 0.61 ± 0.25 (18)
5–28 | 2.03 ± 0.60 (18) | 1.27 ± 0.46 (22) | 2.53 ± 0.67 (18) | 1.39 ± 0.57 (18)
Survival Ratio^b,c^
0 | 0.91 ± 0.02 (18) | 0.96 ± 0.01 (23) | 0.94 ± 0.02 (18) | 0.90 ± 0.03 (18)
1–4 | 0.93 ± 0.04 (18) | 0.90 ± 0.05 (23) | 0.92 ± 0.05 (18) | 0.96 ± 0.02 (18)
5–28 | 0.80 ± 0.06 (18) | 0.87 ± 0.05 (22) | 0.71 ± 0.08 (18) | 0.85 ± 0.06 (18)

^a^ n = the number of pups examined (number of F_1_ litters).

^b^ Data are displayed as the mean of litter values ± standard error of litter values (n = number of litters produced by F_0_ dams); n is dependent on the number of litters produced by the F_0_ generation in which up to two nonindependent F_1_ offspring/sex/litter were selected to produce F_2_ pups through nonsibling mating.

^c^ Statistical analysis performed using the bootstrapped Jonckheere test for trend and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons. All calculations are based on the last litter observation of the day.

Clinical observations noted in individual pups in all exposure groups, including the control group, typically were indicative of an individual pup not thriving and included being cold to touch, pale, no milk in the stomach, and bruising. There was no difference in litter size among the groups (Table 28).

#### F_2_ Body Weights

##### Male Pups

Male pups exposed to EHMC displayed lower pup mean body weights (litter means) with increasing exposure concentration, and the differences among groups became greater over time (Table 29; Figure 26; Appendix E). On PNDs 4 and 10, male pup mean body weight per litter in the 6,000 ppm group was 8% lower relative to the control group (negative trend). A significant decrease in pup mean body weight was first observed in male offspring on PND 13 (decreased 10% relative to the control group), and on PND 28, pup mean body weights were significantly decreased by 14% relative to the control group. These effects are consistent with what was observed in the F_1_ generation.

Table 29 Summary of F_2_ Male and Female Pup Mean Body Weights Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate^a,b^

Postnatal Day | 0 ppm | 1,000 ppm | 3,000 ppm | 6,000 ppm
Male
1 | 6.88 ± 0.09 165 (25)^c^ | 6.78 ± 0.14 208 (33) | 6.63 ± 0.09 167 (24) | 6.68 ± 0.08 159 (25)
4 | 9.61 ± 0.18* 163 (25) | 9.38 ± 0.23 206 (32) | 8.63 ± 0.27* 160 (24) | 8.87 ± 0.22 156 (25)
7 | 13.52 ± 0.41 102 (25) | 13.32 ± 0.41 155 (32) | 12.52 ± 0.39 97 (21) | 12.87 ± 0.44 109 (24)
10 | 19.10 ± 0.63* 96 (25) | 19.14 ± 0.56 139 (32) | 17.45 ± 0.58 91 (21) | 17.64 ± 0.49 99 (23)
13 | 26.35 ± 0.81** 94 (25) | 26.07 ± 0.63 135 (32) | 24.69 ± 0.67 86 (21) | 23.72 ± 0.55** 97 (23)
16 | 33.77 ± 0.99** 94 (25) | 33.16 ± 0.69 133 (32) | 31.63 ± 0.86 86 (21) | 29.46 ± 0.66** 96 (23)
19 | 39.68 ± 1.12** 94 (25) | 39.07 ± 0.83 135 (32) | 37.71 ± 1.00 86 (21) | 34.48 ± 0.73** 96 (23)
21 | 46.17 ± 1.39** 94 (25) | 45.73 ± 1.14 135 (32) | 43.13 ± 1.20 86 (21) | 39.40 ± 0.86** 96 (23)
28 | 78.45 ± 2.28** 94 (25) | 78.20 ± 1.68 135 (32) | 73.29 ± 2.05 86 (21) | 67.29 ± 1.32** 96 (23)
Female
1 | 6.50 ± 0.14 194 (26) | 6.43 ± 0.10 214 (33) | 6.33 ± 0.08 185 (24) | 6.43 ± 0.10 171 (25)
4 | 8.69 ± 0.29 190 (26) | 8.70 ± 0.22 211 (32) | 8.16 ± 0.28 181 (24) | 8.33 ± 0.23 166 (25)
7 | 12.34 ± 0.50 131 (25) | 12.70 ± 0.36 135 (32) | 11.67 ± 0.47 104 (21) | 12.28 ± 0.47 113 (24)
10 | 17.66 ± 0.80 116 (25) | 18.53 ± 0.51 126 (32) | 16.98 ± 0.67 92 (20) | 17.33 ± 0.51 103 (23)
13 | 24.95 ± 0.87** 110 (24) | 24.98 ± 0.65 126 (32) | 24.13 ± 0.76 85 (20) | 23.11 ± 0.54* 102 (23)
16 | 32.29 ± 0.95** 110 (24) | 32.05 ± 0.73 125 (32) | 30.68 ± 0.94 85 (20) | 28.60 ± 0.61** 102 (23)
19 | 37.80 ± 1.12** 110 (24) | 37.73 ± 0.83 125 (32) | 36.48 ± 0.93 85 (20) | 33.49 ± 0.66** 102 (23)
21 | 43.56 ± 1.45** 110 (24) | 43.99 ± 1.06 125 (32) | 41.29 ± 1.16 85 (20) | 38.60 ± 0.85** 102 (23)
28 | 71.21 ± 2.07** 110 (24) | 71.79 ± 1.65 125 (32) | 67.82 ± 1.84 85 (20) | 63.62 ± 1.31** 102 (23)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are displayed as mean ± standard error of the litter means. Body weight data are presented in grams.

^b^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons. Pup weights were adjusted for covariate litter size: total live on postnatal day 1 for day 1 to day 4 and number of live pups poststandardization for later days.

^c^ n = number of pups examined (number of F_1_ litters).

Figure 26

Lactation Growth Curves for F_2_ Male Pups Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate

Information for statistical significance in F_2_ male rat weights is provided in Table 29.

##### Female Pups

Female pups exposed to 6,000 ppm also displayed lower pup mean body weights (litter means) compared to the control group (Table 29; Figure 27; Appendix E). A significant decrease in pup mean body weight was also first observed in female offspring on PND 13 (decreased 7% relative to the control group), and on PND 28, pup mean body weights were significantly decreased by 11% relative to the control group. These effects are consistent with what was observed in the F_1_ generation.

Figure 27

Lactation Growth Curves for F_2_ Female Pups Following Perinatal Exposure to 2-Ethylhexyl p-Methoxycinnamate

Information for statistical significance in F_2_ female rat weights is provided in Table 29.

### Prenatal, Reproductive Performance, and Subchronic Cohorts: Necropsies

#### F_1_ Male Necropsies

F_1_ males in the reproductive performance cohort were euthanized following the mating period corresponding to 160–167 days of age. F_1_ males in the prenatal and subchronic cohorts were euthanized following completion of prenatal pairing corresponding to 110–114 days of age. Terminal mean body weights of rats exposed to 6,000 ppm were significantly decreased relative to the control groups in both the reproductive performance cohort (7%) and the prenatal cohort (5%) (Appendix E); the lower (4%) terminal mean body weight of the 6,000 ppm subchronic cohort males was not significantly different from that of the control group.

Exposed rats in all adult cohorts did not display any gross pathology findings attributable to EHMC exposure. All exposure groups, including the control group, displayed very low incidences of gross pathology findings, none of which exhibited an exposure concentration-response relationship (Appendix E).

In the subchronic cohort, no changes in the weights of the thymus, heart, lungs, or kidneys were directly attributable to EHMC exposure compared to the subchronic control group. Relative liver weight was slightly higher (positive trend) in the 6,000 ppm group males, which was associated with—and attributed to—lower mean body weights (Appendix E). Males in the 6,000 ppm group also displayed significantly decreased absolute and relative ventral prostate gland weights (negative trend and pairwise significance). This response was not observed in either the prenatal or reproductive performance cohorts, which had more animals examined; therefore, lower ventral prostate gland weights were not considered related to EHMC exposure. Rats in the reproductive performance cohort exposed to 3,000 or 6,000 ppm displayed a significant increase (9% and 11%, respectively) in absolute seminal vesicle weights and in relative seminal vesicle weights (14% and 20%, respectively), which was associated with—and attributed to—lower mean body weights (Appendix E). Given that sperm parameters and reproductive endpoints measured in the reproductive performance cohort were not affected by EHMC exposure, these increases in organ weights were not considered toxicologically significant.

#### F_1_ Female Necropsies

F_1_ females and F_2_ offspring in the reproductive performance cohort were euthanized on PND 28, and the F_1_ females were 151–169 days of age at the time of necropsy. Females in the prenatal cohort were 116–132 days of age at the time of necropsy, and females in the subchronic cohort were 111–113 days of age at necropsy. Terminal/adjusted mean body weights at time of necropsy of the 6,000 ppm group, irrespective of cohort, were <5% lower than those of the control groups (Appendix E). No gross findings were attributed to EHMC exposure in any of the cohorts examined (Appendix E).

#### F_2_ Necropsy

Pups were euthanized on PND 28. No findings were attributed to EHMC exposure (Appendix E). A low incidence of bilateral distended ureter was observed in the 6,000 ppm group (two pups from one litter). Unilateral distended ureter (left) was observed in all groups, including the control group (one in each group). This low incidence in all exposed groups is consistent with what was observed in all exposed groups in the prenatal cohort.

### Clinical Pathology

There were significant decreases in alanine aminotransferase (ALT) activity in the 3,000 and 6,000 ppm female rats (Appendix E). The mechanism for the decreased activity is not known but may indicate changes in ALT metabolism; decreases in hepatic enzyme activity have no known toxicological relevance.

### Pathology

No histopathological findings in any of the cohorts were considered related to exposure to EHMC.