# Materials and Methods

## Overview of Pre- and Postnatal Dose Range-finding and Modified One-Generation Study Designs

Modified one-generation (MOG) studies are composed of two interrelated parts: (1) a dose range-finding study (Figure 3) and (2) a MOG study (Table 1; Figure 4). If the acceptable range of exposure concentrations required to avoid excessive general and perinatal toxicity is unknown, a pre- and postnatal dose range-finding study is conducted. Nulliparous females are mated at the animal vendor and sent to the testing laboratory. Dosing typically begins at implantation (gestation day [GD] 6) and continues through weaning which occurred on lactation day (LD) 28. Offspring are exposed in utero, during lactation, and through consumption of dosed feed.

Figure 3

Design of a Dose Range-finding Study

F_0_ dams are exposed to the test article from gestation day (GD) 6 through weaning on lactation day (LD) 28 and evaluated for maternal toxicity. F_1_ offspring are exposed in utero through postnatal day (PND) 28 and evaluated for signs of in utero and postnatal toxicity.

Table 1 Key Modified One-Generation Study Design Endpoints

Cohort | Key Endpoints
F_0_ Dams | Maternal toxicity endpoints (body weight, feed consumption, clinical observations)
F_1_ Generation^a^ | Clinical observations
| Body weights
| Feed consumption
| Necropsy
| Pup survival
| Anogenital distance, nipple/areola retention, testis descent, vaginal cytology
Reproductive Performance Cohort | F_1_ reproductive performance
| F_1_ andrology and sperm parameters
| F_1_ histopathology
| F_2_ litter size, viability, and growth
| F_2_ necropsy
Prenatal Cohort | F_1_ reproductive performance
| F_2_ fetal external, visceral, skeletal, and head soft-tissue examinations
| F_2_ necropsy
Subchronic Cohort | F_1_ hematology
| F_1_ clinical chemistry
| F_1_ histopathology

^a^ Additional cohorts (e.g., biological sampling cohort) and associated endpoints may be included in the study design.

Figure 4

Design of a Modified One-Generation Rat Study

F_0_ dams are exposed to the test article from gestation day (GD) 6 through weaning on lactation day (LD) 28 and evaluated for maternal toxicity. F_1_ offspring are exposed in utero and during lactation through postnatal day (PND) 28 and evaluated for signs of toxicity. After weaning, F_1_ offspring are allocated into cohorts for prenatal, reproductive performance, or additional assessments (e.g., subchronic or biological sampling cohorts) and exposure to test article continues until necropsy. F_2_ offspring are exposed in utero and during lactation and postweaning until necropsy (reproductive performance cohort).

In MOG studies, time-mated females are administered the test article from GD 6 through weaning (evidence of mating = GD 0). The subsequent F_1_ litters are standardized to a specified litter size (n = 8 or 10), with equal representation of both sexes. These offspring are continuously exposed to the test article via the same route of exposure and dose concentration as their dams. Multiple endpoints indicative of potential endocrine alteration (e.g., anogenital distance [AGD], nipple retention in males, pubertal markers) are measured (Table 1). Randomly selected F_1_ animals are taken to adulthood for gross and histopathological examination and can be allocated at weaning (postnatal day [PND] 28) to various cohorts. Histopathological examination of multiple animals per litter increases the power of statistical tests to detect adverse effects.^36^

The ability of F_1_ animals to mate and produce viable offspring is evaluated in the reproductive performance cohort. The potential for the test article to induce fetal defects is assessed in the prenatal cohort. F_2_ fetuses are examined on GD 21, which includes examination of external morphology, fetal viscera, head (soft-tissue and skeletal components), and skeleton (osseous and cartilaginous defects). Abnormalities are categorized as either malformations, which are permanent structural changes that could adversely affect survival, development, or function; or variations, which are a divergence beyond the usual range of structural constitution, but might not adversely affect survival or health,^37^ consistent with descriptions by Makris et al.^38^ Endpoints common to most cohorts are described in Table 1.

Subchronic toxicity, including effects on clinical chemistry and hematology, are assessed in a 3-month cohort. Other cohorts can also be added (e.g., for internal dose estimation, neurobehavioral, toxicokinetic, and/or immunotoxicity assessments) to identify potential hazards across multiple functional outcomes. If necessary, more than one animal per sex can be selected from each litter and assigned to a cohort (e.g., reproductive performance). The F_1_ litter remains the statistical unit but examining multiple animals per litter increases the likelihood of detecting adverse responses and collectively makes the most use of the animals produced.

In the studies reported here, F_0_ females were administered the test article in feed beginning on GD 6. F_1_ and F_2_ offspring were exposed in utero, during lactation, and through consumption of dosed feed.

## Procurement and Characterization

2-Ethylhexyl p-methoxycinnamate (EHMC) was obtained from Acros Organics (Fair Lawn, NJ) in a single lot (A0293319). Identity, purity, and stability analyses were conducted by the analytical chemistry lab at MRIGlobal (Kansas City, MO) (Appendix A). Reports on analyses performed in support of the EHMC study are on file at the National Institute of Environmental Health Sciences (NIEHS).

EHMC is a clear, colorless liquid. The identity of lot A0293319 was evaluated using Fourier Transform infrared (FT-IR) spectroscopy, ^1^H nuclear magnetic resonance (NMR) spectroscopy, ^13^C NMR spectroscopy, and gas chromatography (GC) with mass spectrometry (MS) (Table A-1).

The FT-IR, ^1^H NMR, and ^13^C NMR spectra (Appendix A) were consistent with the structure of EHMC and reference spectra for the trans-isomer in the National Institute of Advanced Industrial Science and Technology Spectral Database (No. 19199). The GC/MS spectra corresponded with the National Institute of Standards and Technology Mass Spectral Library reference for EHMC.

Elemental analysis was consistent with the composition of EHMC. Karl Fisher titration indicated a water content of <0.1%. The purity of lot A0293319 determined using GC with flame ionization detection (FID) with two different column chemistries was 99.17% and 98.99% (Table A-1). Both methods identified three impurities having an area ≥0.05%. The purity of lot A0293319 was determined to be >98%.

Accelerated stability studies confirmed that the bulk lot A0293319 was stable when protected from light and stored for 2 weeks at approximately 5°C, 25°C, 60°C, or −20°C. Upon receipt by the analytical laboratory, the 150 kg drum of lot A0293319 was homogenized and transferred to 1-gallon narrow-mouthed amber glass bottles sealed with Teflon-lined lids. Periodic reanalysis of the bulk chemical performed during and after the studies showed no degradation.

## Preparation and Analysis of Dose Formulations

Dose formulations of EHMC in LabDiet 5K96 Verified Casein Diet 10 IF feed were prepared following the protocols outlined in Table A-2. Dose formulations of 1,000, 3,000, and 6,000 ppm were used for the modified one-generation study. Formulations were stored at approximately 5°C and were considered stable for 35 days.

The method of preparation was validated for concentration ranges of 400–25,000 ppm.

Prior to study start, the stability and homogeneity of the dose formulations were determined using GC/FID. Stability of the 1,000 ppm formulation was confirmed for 35 days at refrigerated temperatures (5°C). A 7-day simulated dose study of the 1,000 ppm formulation was conducted to determine stability in animal room conditions. Formulations mixed with rodent urine and feces were stable for up to 4 days at a concentration of 1,000 ppm. Homogeneity of the dose formulations was confirmed at 1,000, 2,250, and 20,000 ppm.

Analyses of preadministration and postadministration dose formulations were conducted throughout the study. Postadministration samples were collected from the animal room at the end of the first exposure period. All samples were within 10% of the target concentration with the exception of three postadministration formulations from the dose range-finding study (Table A-3, Table A-4).

## Animal Source

Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc, Indianapolis, IN and Dublin, VA) for use in the dose range-finding and MOG studies. Sexually mature (12 to 14 weeks old) females were time-mated overnight at the vendor and were received on GD 1 or GD 2 for both the dose range-finding and MOG studies. GD 0 was defined as the day positive evidence of mating was observed.

## Animal Health Surveillance

In accordance with the National Toxicology Program (NTP) Sentinel Animal Program (Appendix C), 10 female sentinel animals were evaluated in the dose range-finding study. Twenty female sentinel and 10 F_1_ male animals were evaluated in the MOG study. All test results were negative.

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Laboratory Animals. All animal studies were conducted in a facility accredited by AAALAC International. Studies were approved by the RTI International Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Experimental Design

### Dose Range-finding Study

Time-mated female rats were received on GD 1 or GD 2, randomized based on GD 3 body weight, and placed on a 5K96 Casein diet containing 0, 2,250, 5,000, 10,000, or 20,000 ppm of EHMC on GD 6 through LD 28. Feed and water were available ad libitum. Information on feed composition and contaminants is provided in Appendix B. The high exposure concentration of 20,000 ppm was estimated to result in a daily “limit” oral dose of at least 1 g EHMC/kg body weight/day. Half-dose spacing was used to identify a maximally tolerated dose that the dam could tolerate and so the MOG study could be populated with a sufficient number of offspring. Altering the concentration of EHMC in the diet, reflecting changes in feed consumption as a function of time and life stage, was considered. However, this approach was ultimately overridden, given the challenges of having multiple feed concentrations at an anticipated projected daily dose level and different life stages.

Eight time-mated females were allocated to each exposure group. Six additional time-mated females were allocated to the control, 2,250, and 20,000 ppm EHMC groups for collection of tissues for bioanalytical method development. Viability, clinical observations, body weights, pup counts (litters were not standardized), and feed consumption were recorded to help determine the maximum exposure concentration that could be tolerated by the dams while not severely decreasing litter size and resulting in an insufficient number of pups available for postnatal assessments and cohort-specific endpoints. Further details of animal maintenance and study design are given in Table 2.

Table 2 Experimental Design and Materials and Methods in the Dose Range-finding and Modified One-Generation Studies of 2-Ethylhexyl p-Methoxycinnamate (Preweaning)

Dose Range-finding Study | Modified One-Generation Study
Study Laboratory
RTI International (Research Triangle Park, NC) | Same as dose range-finding study
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Same as dose range-finding study
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | Envigo (formerly Harlan Laboratories, Inc., Dublin, VA)
Day of Arrival
February 14, 2012 (GD 1 or GD 2) | September 25 or 27, 2012 (GD 1 or GD 2)
Average Age on Arrival
~12 weeks | 12–14 weeks
Weight Range at Randomization
192.8–249.5 g on GD 3 | 199.8–257.0 g on GD 3
Date of First Exposure
GD 6 (February 18, 2012) | F_0_ females: GD 6 (September 29, 2012)
| F_1_ rats (all cohorts): lifetime exposure
| F_2_ rats: lifetime exposure
Duration of Exposure
GD 6 through LD 28 | F_0_ females: GD 6 through LD 28
| F_1_ rats (biosampling cohort): lifetime exposure through PND 56
| F_1_ rats (subchronic cohort): lifetime exposure through PND 110–112 (males) or through PND 111–113 (females)
| F_1_ rats (prenatal cohort): lifetime exposure through PND 112–114 (males) or through PND 116–132 (females)
| F_1_ rats (reproductive performance cohort): lifetime exposure through PND 160–167 (males) or through PND 151–169 (females)
| F_2_ rats (reproductive performance cohort): in utero through PND 28
Date of Last Exposure
LD 28 (April 4, 2012) | F_0_ females: LD 28 (November 15, 2012)
| F_1_ rats (biosampling cohort): PND 56 (December 12, 2012)
| F_1_ rats (subchronic cohort): PND 110–112 (February 4, 2013) (males) or PND 111–113 (February 5, 2013) (females)
| F_1_ rats (prenatal cohort): PND 112–114 (February 7, 2013) (males) or PND 116–132 (February 24, 2013) (females)
| F_1_ rats (reproductive performance cohort): PND 160–167 (April 1, 2013) (males) or PND 151–169 (April 3, 2013) (females)
| F_2_ rats (reproductive performance cohort): PND 28 (through April 3, 2013)
Necropsy Dates
Gross necropsies were conducted on F_0_ females that did not deliver a litter and F_1_ offspring euthanized moribund or found dead. | F_0_ females: LD 28 (November 12–15, 2012)
| F_1_ rats (biosampling cohort): not performed
| F_1_ rats (subchronic cohort): PND 110–112 (February 4, 2013) (males) or PND 111–113 (February 5, 2013) (females)
| F_1_ rats (prenatal cohort): PND 112–114 (February 6–7, 2013) (males) or GD 21 (February 11–24, 2013) (females)
| F_1_ rats (reproductive performance cohort): PND 160–167 (March 26–April 1, 2013) (males) or LD 28 (March 19–April 2, 2013) (females)
| F_2_ rats (reproductive performance cohort): March 19–April 3, 2013
Average Age at Necropsy
Not performed | F_0_ females: ~21 weeks
| F_1_ rats (biosampling cohort): not performed
| F_1_ rats (subchronic cohort): 110–112 days (males) or 111–113 days (females)
| F_1_ rats (prenatal cohort): 112–114 days (males) or 116–132 days (females)
| F_1_ rats (reproductive performance cohort): 160–167 days (males) or 151–169 days (females)
| F_2_ rats (reproductive performance cohort): 28 days
Size of F_0_ Study Groups
8–14 time-mated females | 26 time-mated females
Method of Randomization and Identification
Time-mated animals were individually identified by ink tail marking and assigned to exposure group by stratified randomization of GD 3 body weights using Provantis^®^ (Instem, Stone, United Kingdom) electronic data collection system. | Same as dose range-finding study, except F_1_ and F_2_ pups were identified by ink paw marking, and postweaning F_1_ males and F_1_ females were identified by ink tail marking.
Animals per Cage
1 (with litter) | F_0_ females: 1 (with litter)
| F_1_ rats (biosampling, subchronic, and prenatal cohorts): ≤2 (males and females)
| F_1_ rats (reproductive performance cohort): ≤2 until PND 91, then housed individually except during cohabitation or when housed with their litters
Diet
Irradiated certified Advanced Protocol Verified Casein Diet 1 IF 5K96 (PMI Nutrition International, St. Louis, MO), available ad libitum | Same as dose range-finding study
Water
Tap water (Durham, NC) via automatic watering system (Avidity Science, formerly Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as dose range-finding study
Cages
Solid bottom polycarbonate cages (Lab Products, Inc., Seaford, DE), rotated biweekly and changed at least once/week | Same as dose range-finding study
Bedding
Certified irradiated Sani-Chips^®^ hardwood cage bedding (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly | Same as dose range-finding study
Cage Filters
Filter paper (Granville Milling Co., Creedmoor, NC), changed biweekly | Same as dose range-finding study
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks during the study | Same as dose range-finding study
Animal Room Environment
Temperature: 71°F ± 2°F Relative humidity: 49.5% ± 5% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Exposure Concentrations
0, 2,250, 5,000, 10,000, or 20,000 ppm EHMC in feed, available ad libitum | 0, 1,000, 3,000, or 6,000 ppm EHMC in feed, available ad libitum
Type and Frequency of Observation of F_0_ and F_1_ Dams
Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. Female body weights were recorded daily during gestation (GD 3–21) and during lactation on LDs 1, 4, 7, 14, 21, 25, and 28. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21, and for LDs 1–4, 4–7, 7–14, 14–21, 21–25, and 25–28. | Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. Female body weights were recorded daily during gestation (GD 3–21) and during lactation on LDs 1, 4, 7, 10, 13, 16, 19, 21, 25, and 28. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21, and for LDs 1–4, 4–7, 7–14, 14–21, 21–25, and 25–28.
Type and Frequency of Observation of F_1_ and F_2_ Pups
Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. The number of live and dead pups in each litter was counted daily. Individual pups were sexed and weighed on PNDs 1, 4, 7, 14, 21, 25, and 28. Litters were not standardized on PND 4, and all offspring (unless euthanized and biological samples collected for subsequent analytical method development) were retained until PND 28 to assess litter size, sex distribution, pup body weights, and survival during lactation. | Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. The number of live and dead pups in each litter was counted daily. Individual pups were sexed and weighed on PNDs 1, 4, 7, 10, 13, 16, 19, 21, 25, and 28. Litters were standardized to a litter size of 10 pups (5/sex/litter, when possible) on PND 4. Endocrine F_1_/F_2_ endpoints: AGD and corresponding pup weight on PND 1; areolae/nipple retention on PND 13; testicular descent beginning on PND 14
Primary Method of Euthanasia
100% carbon dioxide (F_0_ females and PND 28 pups); intraperitoneal injection of a solution containing sodium pentobarbital or decapitation (PND 4 pups) | 100% carbon dioxide with puncture of the diaphragm (adults and PND 28 pups) or intraperitoneal injection of a solution containing sodium pentobarbital (≤PND 12 pups and fetuses)
Necropsy and Postmortem Evaluation
F_0_ dams were euthanized on LD 28 without necropsy. Females that did not litter were euthanized ~5 days after expected littering, received a gross necropsy, and had their pregnancy status determined. If present, the numbers of implantation sites and corpora lutea were recorded. F_1_ pups that were removed for health reasons or died received a gross necropsy. | F_0_ dams were euthanized on LD 28, received a gross necropsy, and had their number of implantation sites recorded. Females that did not litter were euthanized 3 days after expected littering, received a gross necropsy, and had their pregnancy status determined. If present, the number of implantation sites and corpora lutea was recorded. Histopathological analysis of gross lesions was performed if collected.
Internal Dose Assessment/Additional Tissue Collection
On GD 18, maternal plasma, amniotic fluid, and fetuses were collected from three pregnant dams/exposure group from the 0, 2,250, and 20,000 ppm groups. On LD 4, maternal plasma was collected from 3 dams/exposure group from the 0, 2,250, and 20,000 ppm groups. On PND 4, pups (3/sex) were collected from 3 dams/exposure group from the 0, 2,250, and 20,000 ppm groups. On LD 28, maternal plasma was collected from three dams/exposure group from the 0, 2,250, and 20,000 ppm groups. None of the internal dose assessment samples were analyzed because in a preliminary investigation, it was observed that EHMC was not stable under the conditions used for sample collection and storage. | On PNDs 28 and 56 (5/sex/time point/exposure group), kidneys, epididymides, testes, ovaries, and liver were collected from rats in the biological sampling cohort and frozen for potential future analyses. Plasma samples were also collected from these rats on PNDs 28 and 56 (5/sex/time point/exposure group) for potential EHMC analyses. None of the internal dose assessment samples were analyzed because in a preliminary investigation, it was observed that EHMC was not stable under the conditions used for sample collection and storage.

GD = gestation day; LD = lactation day; PND = postnatal day; EHMC = 2-ethylhexyl p-methoxycinnamate; AGD = anogenital distance.

### Modified One-Generation Study with Prenatal, Reproductive Performance, and Subchronic Cohorts

Time-mated F_0_ female rats, 26 per group, were received on GDs 1 or 2, randomized based on GD 3 body weight, and placed on a 5K96 Casein diet containing 0, 1,000, 3,000 or 6,000 ppm EHMC ad libitum on GD 6. The exposure concentration of 6,000 ppm was expected to result in minimal maternal toxicity and to ensure that the model system was appropriately challenged, increasing the likelihood of identifying any toxicological signal in the offspring. The F_1_ and F_2_ generations were exposed to EHMC via the mother during gestation and lactation and directly via 5K96 feed at the same exposure concentration as their respective dams. Viability, clinical observations, body weights, pup counts, and feed consumption were recorded. F_1_ and F_2_ litters were standardized to 10 pups (5/sex/litter, when possible) on PND 4. At weaning on PND 28, F_1_ offspring were randomly assigned to a reproductive performance (up to 2/sex/litter, when available), prenatal (1/sex/litter), subchronic (1/sex from 10 litters), or biological sampling cohort (1/sex/litter). Information on feed composition and contaminants is provided in Appendix B. Additional details of animal maintenance and study design are given in Table 2.

#### Endocrine-sensitive and Pubertal Endpoints

AGD and corresponding body weight (for covariate analyses) were recorded for each F_1_ and F_2_ pup on PND 1 (PND 1 is the day after parturition is completed). AGD was measured using a stereomicroscope with a calibrated ocular reticle by a limited number of individuals that demonstrated uniformity and consistency of measurements. The distance between the midpoint of the anal opening to the caudal edge of the genital papilla was recorded and converted to millimeters (mm). F_1_ and F_2_ male pups were evaluated for retention of areolae/nipples on PND 13 and observed for testicular descent over 26 (F_1_) or 28 (F_2_) days beginning on PND 14. Acquisition of balanopreputial separation (BPS), defined as complete retraction of the prepuce from the glans penis, was evaluated in all F_1_ males over 59 days beginning on PND 35, and body weight was recorded upon BPS acquisition. External genitalia were examined for malformations and undescended testes (cryptorchidism). The acquisition of vaginal opening (VO) was evaluated in F_1_ females over 48 days beginning on PND 23, and the corresponding body weight recorded upon VO acquisition.

#### Vaginal Cytology

Beginning on PND 75, vaginal lavages were collected from the F_1_ females in the prenatal, reproductive performance, and subchronic cohorts for 16 consecutive days for evaluation of estrous cyclicity and confirmation of mating. Vaginal vaults were moistened with saline, if necessary, and samples of vaginal fluid and cells were spotted onto a slide and subsequently stained with toluidine blue. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stages (diestrus, proestrus, estrus, and metestrus).^39^

#### F_1_ Cohabitation and Assessment of Mating

Sexually mature F_1_ animals in the prenatal (14–15 weeks; 1 male and 1 female/litter) and reproductive performance (17–18 weeks; 2 males and 2 females/litter) cohorts were randomly assigned a mating partner, avoiding sibling pairings, and paired in a 1:1 ratio for ≤15 days. Mating was confirmed by daily examination for the presence of a vaginal copulation plug or sperm in a vaginal lavage. The day of confirmed mating was considered GD 0. Females that did not exhibit evidence of mating or did not deliver a litter were necropsied 25 days after the cohabitation period ended. The uterus was examined grossly and stained with ammonium sulfide to identify potential implantation sites. The number of corpora lutea on the ovary was enumerated, and gross lesions were examined for histopathological changes.

#### Prenatal Cohort

On GD 21, F_2_ fetuses were removed from the uterus, individually weighed (live fetuses only), and examined externally for alterations, including inspection of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were subsequently euthanized with oral administration of sodium pentobarbital. F_1_ females with no evidence of mating were necropsied and examined for gross lesions, which were retained and examined histologically. Fetal sex was confirmed by inspection of gonads in situ. All F_2_ fetuses in each litter were examined for soft tissue alterations under a stereomicroscope.^40,41^ The heads were removed from approximately half of the fetuses in each litter, fixed in Bouin’s solution, and subsequently examined by freehand sectioning.^42^ This technique precludes skeletal evaluations of the skull; therefore, remaining heads and all fetuses were eviscerated, fixed in ethanol, macerated in potassium hydroxide, stained with Alcian blue and Alizarin red, and examined for subsequent cartilage and osseous alterations.^43,44^ External, visceral, and skeletal fetal findings were recorded as developmental variations or malformations. After positive evidence of mating, male sires were euthanized and necropsied, selected organs were weighed, and gross lesions were collected for potential histological examination.

#### Reproductive Performance Cohort

Fertility and fecundity were assessed in two males and two females from each F_1_ litter and all exposure groups. Pup viability was assessed daily during lactation. F_2_ offspring were standardized to a litter size of 10 pups (5/sex/litter, when possible) on PND 4. F_1_ males were euthanized at approximately 23–24 weeks of age after assessment of fertility, fecundity, and F_2_ generation pup survival. The F_1_ females and the F_2_ offspring were euthanized on PND 28, when the F_1_ females were 22 weeks of age. F_2_ offspring were given a gross necropsy. F_1_ sires were euthanized and necropsied after mating, selected organs were weighed, and gross lesions were collected for potential histological examination. Given the absence of functional changes, a crossover mating to determine affected sex was deemed unnecessary.

Immediately after euthanasia, the left testis and epididymis were removed, trimmed, and weighed. The cauda epididymis was then weighed, and samples were collected for determining cauda epididymal sperm motility, number, and density via automated sperm analyzer (Hamilton Thorne, Inc., Beverly, MA). The sampled left cauda epididymis and the intact corpus and caput were frozen at approximately −80°C for subsequent determination of epididymal sperm concentration from the left cauda epididymis. The left testis was frozen at approximately −80°C for subsequent determination of homogenization-resistant spermatid head counts for calculations of daily sperm production and efficiency of daily sperm production.^45^ The right testis and epididymis were examined histologically. Gross lesions took precedence over sperm parameter assessments (i.e., if the left testis was grossly abnormal, it and the left epididymis would be examined histologically, and the right testis and epididymis, if grossly normal, would be subjected to sperm assessments).

#### Subchronic Cohort

General toxicity was assessed in one male and one female from 10 random litters (within an exposure concentration) and all exposure groups. F_1_ males and females were euthanized and necropsied on PND 110 to PND 112 and PND 111 to PND 113, respectively. The animals were anesthetized with carbon dioxide and euthanized by exsanguination. Blood was collected by cardiac puncture. Blood for hematology was collected into a tripotassium ethylenediaminetetraacetic acid (K_3_EDTA)-treated tube and analyzed on an Advia 120 hematology analyzer (Erlangen, Germany). Blood for clinical chemistry analyses was collected into a serum separator tube and the serum harvested and analyzed on an Olympus 640e clinical chemistry analyzer (Center Valley, PA). The samples for clinical pathology analyses were stored at approximately 4°C until transferred to Antech^®^ GLP (Morrisville, NC) on the same day as necropsy for the clinical pathology analyses. The parameters measured are listed in Table 3.

Table 3 Experimental Design and Materials and Methods in the Modified One-Generation Study of 2-Ethylhexyl p-Methoxycinnamate (Postweaning)

Modified One-Generation Study
F_1_ Postweaning Assessments
All Cohorts: Viability was assessed at least twice daily, and clinical observations recorded at least once daily. F_1_ male body weights and feed consumption were recorded once weekly. F_1_ female body weights and feed consumption were recorded at least once weekly during the premating interval. Vaginal opening (and concomitant body weight) was evaluated beginning on PND 23, and balanopreputial separation (and concomitant body weight) was evaluated beginning on PND 35.
Prenatal and Reproductive Performance Cohorts: After collection of vaginal lavage samples for 16 days, F_1_ nonsibling mating pairs (1 male and 1 female/litter [prenatal cohort] or 2 males and 2 females/litter [reproductive performance cohort]) from the same exposure group were cohabitated until evidence of mating or for ≤15 days. F_1_ dams were observed for the same gestational endpoints as the F_0_ dams.
Reproductive Performance Cohort: F_1_ dams and F_2_ pups were evaluated for the same lactational endpoints as the F_0_ dams and F_1_ pups. A crossover mating would have been considered if an effect on fertility was observed.
F_1_ Necropsy and Postmortem Evaluation
Prenatal Cohort: F_1_ dams were euthanized on GD 21. Necropsies were performed on all females. Terminal body weights and adrenal glands (paired), ovaries (left and right), and gravid uterus weights were recorded. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses and resorptions (early or late) and the total number of implantation sites were recorded. If there was no macroscopic evidence of pregnancy, the uterus was stained to visualize potential evidence of implantation sites. Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities, including examination of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were euthanized and then examined for visceral morphological abnormalities by fresh dissection. The sex of each fetus was confirmed by internal examination. The heads from approximately one-half of the fetuses in each litter were fixed, sectioned, and examined. All fetuses were eviscerated, fixed, stained, and examined for skeletal developmental variations, malformations, or other morphological findings. After positive evidence of mating, male sires were weighed, euthanized, and necropsied, and the following organ weights recorded: adrenal glands (paired), testes (left and right), epididymides (left and right), dorsolateral and ventral prostate, seminal vesicles with coagulating glands, thyroid gland (fixed), LABC muscle, Cowper’s glands (paired), and preputial glands. Histopathology of gross lesions was assessed.
Reproductive Performance Cohort: F_1_ dams were euthanized on LD 28, and sires were euthanized within approximately a week of their mating partner. Terminal body weights and the following organ weights were recorded: adrenal glands (paired), ovaries (left and right), testes (left and right), epididymides (left and right), cauda epididymis, dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, thyroid gland (fixed), LABC muscle, Cowper’s glands (paired), and preputial glands. Histopathology was performed on the following organs (predominantly reproductive tissues): adrenal glands, liver, kidneys, pituitary gland, thyroid gland, ovaries, uterus, vagina, testis, epididymis, dorsolateral and ventral prostate gland, seminal vesicles, coagulating glands, LABC muscle, Cowper’s glands (paired), preputial glands, and gross lesions. Cauda epididymal sperm motility, cauda epididymal sperm concentration, and testicular sperm head counts were also assessed.
Biological Sampling Cohort: At weaning, F_1_ rats were randomly allocated for collection of biological samples. Rats were subjected to a gross necropsy and the following tissues were collected on PNDs 28 and 56 (5/sex/time point/exposure group): plasma, kidneys, epididymides, testes, ovaries, and liver. Tissues were frozen at approximately −70°C until analysis.
Subchronic Cohort: F_1_ males and females were euthanized on PND 110–112 and PND 111–113, respectively. Blood was collected for hematology, clinical chemistry analyses, and micronucleus determination. The following hematology parameters were analyzed: erythrocyte count, hemoglobin concentration, hematocrit, mean corpuscular volume, mean corpuscular hemoglobin, mean corpuscular hemoglobin concentration, leukocyte count and differential, reticulocyte count, and platelet count. The following clinical chemistry parameters were analyzed: total protein, albumin, urea nitrogen, creatinine, alanine aminotransferase, sorbitol dehydrogenase, alkaline phosphatase, bile acids, glucose, creatine kinase, cholesterol, and triglycerides. The following organ weights were recorded: epididymides (right and left), heart, kidney (right and left), liver, lungs, dorsolateral prostate gland, ventral prostate gland, seminal vesicles with coagulating glands, testis (right and left), and thymus. In addition to gross lesions, histopathology was performed on the following organs: adrenal glands (paired), bone with marrow, brain, cervix, clitoral glands, epididymides (paired), esophagus, eyes, Harderian glands, heart and aorta, kidneys (paired), large intestine (cecum, colon, and rectum), liver, lungs, lymph nodes (mandibular and mesenteric), mammary glands, nose, ovaries (paired), pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicles with coagulating gland, skin, small intestine (duodenum, jejunum, and ileum), spleen, stomach (forestomach and glandular), testes (paired), thymus, thyroid gland, trachea, urinary bladder, uterus, vagina, and Zymbal’s glands.

PND = postnatal day; GD = gestation day; LABC = levator ani/bulbocavernosus; LD = lactation day.

In addition, approximately 200 μL of whole blood was collected into a K_3_EDTA-treated tube for micronucleus determination. The micronucleus samples were stored at approximately 4°C until transferred to the designated NTP laboratory (Integrated Laboratory Systems, LLC, Durham, NC) on the same day as the necropsy.

#### Biological Sampling Cohort

On PND 28 and PND 56 (5/sex/time point/exposure group), plasma, kidneys, liver, epididymides, testes, and ovaries were collected and frozen for potential future analyses. None of the internal dose assessment samples were analyzed because in a preliminary investigation, it was observed that EHMC was not stable under the conditions used for sample collection and storage.

#### Necropsy and Histopathology

Complete necropsies were performed on adult F_1_ male and F_1_ females in the subchronic and reproductive performance cohorts, unscheduled deaths, F_0_ females, F_1_ males and F_1_ females in the prenatal cohort, F_1_ females in the reproductive performance cohort that either had no evidence of mating or did not produce a litter, and F_2_ offspring. All gross lesions were examined histologically. In addition, several protocol-required tissues were examined microscopically from the adult F_1_ male and F_1_ females in the subchronic and reproductive performance cohorts. In the prenatal cohort, organ weights were recorded for the adrenal glands, testes, epididymides, dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, thyroid gland (fixed), levator ani/bulbocavernosus (LABC) muscle, Cowper’s glands, and preputial glands. In the reproductive performance cohort, organ weights were recorded for the adrenal glands, ovaries, testes, epididymides, cauda epididymis, dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, thyroid gland (fixed), LABC muscle, Cowper’s glands, and preputial glands. In the subchronic cohort, organ weights were recorded for the epididymis, heart, kidney, liver, lungs, dorsolateral prostate gland, ventral prostate gland, seminal vesicles with coagulating glands, testes, and thymus.

The initial histological examination was performed by an experienced, board-certified veterinary pathologist. The slides, individual animal data records, and pathology tables were subsequently evaluated by an independent quality assessment (QA) laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. A QA pathologist evaluated selected slides from the various cohorts. For the F_1_ subchronic males and females, all diagnoses from all tissues from six randomly selected animals in the control and 6,000 ppm groups were reviewed. In addition, the dorsal prostate gland, ventral prostate gland, epididymides, and testes were reviewed from all control and 6,000 ppm males in the F_1_ subchronic and F_1_ reproductive performance cohorts; the ovaries and uterus were reviewed from all control and 6,000 ppm females in the F_1_ subchronic and F_1_ reproductive performance cohorts.

The QA report and the reviewed slides were submitted to the NTP pathologist, who reviewed and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologist. The QA pathologist, who served as the coordinator of the Pathology Working Group (PWG) presented representative histopathology slides containing examples of lesions related to test article administration, examples of disagreements in diagnoses between the laboratory and QA pathologist, or lesions of general interest to the PWG for review. The PWG consisted of the NTP pathologist and other pathologists experienced in rodent toxicological pathology. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, QA pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^46^ and Boorman et al.^47^

## Statistical Methods

Statistical methods were chosen based on distributional assumptions as well as on the need to incorporate within-litter correlation among animals. Unless specifically mentioned, all endpoints were tested for a trend across exposure groups, followed by pairwise tests for each exposed group against the control group. Significance of all trend and pairwise tests is reported at both 0.05 and 0.01 levels.

### Analysis of Fetal Malformations and Variations

Incidences of malformations and variations in fetuses were summarized as number of litters affected and as number of fetuses affected. Trend and pairwise analysis of the fetal malformations and variations was conducted using a Cochran-Armitage test with a Rao-Scott adjustment, as described below.

The tendency of fetuses from the same litter to respond more similarly than fetuses from different litters has been referred to as the “litter effect”^48^ and reflects littermates’ similarities in genetics and in utero experiences. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Therefore, the Cochran-Armitage test was modified to accommodate litter effects using the Rao-Scott approach.^49^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Cochran-Armitage test as recommended by Fung et al.,^50^ formula ₸_RS2_.

### Analysis of Incidences of Gross Pathology and Morphology Findings

For the F_0_ dams, incidences of gross findings and histopathology were summarized as number of animals affected. Because some of these animals did not survive until the removal day for their cohort, analysis of the histopathological findings was conducted using the Poly-3 test, as described below.

The Poly-k test^51-53^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage trend test to account for survival differences. Following Bailer and Portier,^51^ a value of k = 3 was used in the analysis of site-specific lesions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^54^ Poly-3 tests used the continuity correction described by Nam.^55^

For the F_1_ and F_2_ animals, incidences of gross findings and histopathology were summarized as number of litters affected and number of animals affected. To account for within-litter correlation, the Rao-Scott adjustment (as described earlier) was applied to the Cochran-Armitage test in the analysis of this data. For histopathological data in F_1_ cohorts in which survival issues could apply, the Poly-3 correction was also applied.

All p values calculated for gross pathological and histopathological data are one-sided and include a continuity correction.

### Analysis of Continuous Endpoints

Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey^56^ for small samples (n < 20) and Tukey’s outer fences method^57^ for large samples (n ≥ 20) were examined by NTP personnel, and implausible values were eliminated from the analysis.

In some instances, no considerations for litter effects were necessary in the analysis of the continuous data. This was the case for the F_0_ generation and for the F_1_ prenatal cohort for which there was only one animal per litter. In these instances, organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^58^ and Williams.^59,60^

When litter effects were present, organ and body weight endpoints were analyzed using linear mixed models, with litters as a random effect. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^61^ Pup and fetal weights were adjusted for litter size by covariate analysis (see below) before analysis. AGD was adjusted for the body weight of the pup taken on the day of AGD measurement. The adjusted AGDs were analyzed as normal variates with litter effects using a linear mixed model.

Feed consumption, litter sizes, pup survival, implantations, number of resorptions, uterine content endpoints, spermatid, and epididymal spermatozoal measurements typically have skewed distributions. When litter effects were not present, these endpoints were analyzed using the nonparametric multiple comparison methods of Shirley^62^ (as modified by Williams^63^) and Dunn.^64^ For these endpoints, the Jonckheere test^65^ was used to assess the significance of the exposure concentration-related trends and to determine, at the 0.01 level of significance, whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test).

When litter effects were present for nonnormally distributed continuous endpoints, the trend across exposure groups was analyzed by a permutation test based on the Jonckheere trend test implemented by randomly permuting whole litters across exposure groups and bootstrapping within the litters (see, for example, Davison and Hinckley^66^). Pairwise comparisons were made by using a modified Wilcoxon test that incorporated litter effects.^67^ The Hommel procedure was used to adjust for multiple comparisons.^68^

### Analysis of Feed Consumption Data

Feed consumption was measured at 3-day intervals for F_0_ and F_1_ dams during gestation and lactation and at least weekly thereafter. In some cases, consumption is reported over intervals that span multiple measurements (e.g., GD 6–21 and LD 1–14). These long-interval values are calculated at the animal or cage level using a weighted average of available constituent subinterval measurements, which are weighted by the underlying subinterval lengths. When spillage is noted or an outlier value is removed from the analysis, the subinterval value for the animal is not reported, and the long interval is calculated excluding that subinterval. As a result, there may be instances in which more animals are reported for a long interval (e.g., GD 6–21) than are reported for the constituent subintervals (GD 6–9, GD 9–12, etc.).

### Analysis of Gestational and Fertility Indices

When litter effects were not present, Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across exposure groups. Fisher’s exact test was used to conduct pairwise comparisons of each exposed group with the control group. P values for these analyses are two-sided.

When litter effects were present, as with the F_1_ reproductive performance cohort, the gestational and fertility indices were tested using the Rao-Scott adjustment to the Cochran-Armitage test. This practice was used for both the trend and pairwise tests.

### Body Weight Adjustments

Because body weights typically decrease with increasing litter size, adjusting body weight for litter size in the analysis of fetal and pup weights can provide additional precision to detect test article effects.^69^ Body weight adjustments are appropriate when the litter effect, as evidenced by decreasing weights with increasing litter size, is relatively constant across exposure concentrations. Adjusted fetal weights were calculated by fitting a linear model to litter mean fetal weights as a function of litter size and exposure concentration, and the estimated coefficient of litter size was then used to adjust each litter mean fetal weight based on the difference between its litter size and the mean litter size. Preweaning pup body weights were adjusted for live litter size as follows. A linear model was fit to body weights as a function of exposure concentration and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight based on the difference between its litter size and the mean litter size. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 21 were adjusted for PND 4 poststandardization litter size. After adjustment, mean body weights were analyzed with a linear mixed model with a random litter effect.

### Analysis of Time-to-event Data

Time-to-event endpoints, such as day of attainment of testicular descent, BPS, and VO, have four features that require careful model selection: (1) they might display nonnormality; (2) litter-based correlation might be present; (3) values might be censored, meaning attainment is not observed before the end of the observation period; and (4) growth retardation, reflected in the weaning weight, is an important covariate in the case of BPS and VO given the relationship between normal day of expected attainment and body weight.

A mixed model was fit to attainment day as a function of exposure concentration as well as a function of both exposure concentration and weaning weight (for BPS and VO) with a random litter effect; this approach is adequate when attainment times are approximately normally distributed, and attainment is observed for all animals. Censored observations were not included in mixed models. For multiple comparisons, Dunnett-Hsu adjustments were used for mixed models.

To calculate mean attainment values adjusted for weaning weight, a linear model was fit to attainment day as a function of exposure and weaning weight. The estimated coefficient of weaning weight was then used to adjust each attainment day based on the difference between the measured weaning weight and the mean weaning weight.

Cumulative response percent, obtained using the methods of Kaplan-Meier, was plotted against time to attainment for unadjusted attainment times as well as attainment times adjusted for weaning weight. For litter-based plots, the litter median was used as time to attainment if >50% of the pups for that litter attained. Otherwise, litters with ≤50% of the pups attaining had time to attainment set to the final day of observation. These litters are included in the denominator of Kaplan-Meier calculations but not the numerator.

### Analysis of Vaginal Cytology Data

Vaginal cytology data consist of daily observations of estrous cycle stages over a 16-day period. Differences from the control group for cycle length and number of cycles were analyzed using a Datta-Satten modified Wilcoxon test with a Hommel adjustment for multiple comparisons.

To identify disruptions in estrous cyclicity, a continuous-time Markov chain model (multi-state model) was fit using a maximum likelihood approach,^70^ producing estimates of stage lengths for each exposure concentration group. Confidence intervals for these estimates were obtained based on bootstrap sampling of the individual animal cycle sequences. Stage lengths that were significantly different from the control group were identified using permutation testing with a Hommel adjustment.

### Historical Control Data

The concurrent control group is the most valid comparison to the exposed groups and is the only control group analyzed statistically in NTP developmental and reproductive toxicity studies. However, historical control data are often helpful in interpreting potential exposure concentration-related effects, particularly for uncommon fetal findings that occur at a very low incidence. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Factors that might affect the background incidences of fetal findings at a variety of sites are diet, strain/stock, route of exposure, study type, and/or laboratory that conducted the study. The NTP historical control database for fetal findings contains all fetal evaluations from teratology studies and/or modified one-generation studies for each laboratory. In general, the historical control database for a given study includes studies using the same route of administration and study design. However, historical control data for rats in this NTP Developmental and Reproductive Toxicity Technical Report contain data from feed and gavage (all routes) studies conducted at RTI International. The concurrent controls are included in the historical control data set. NTP historical controls are available online at https://ntp.niehs.nih.gov/data/controls/index.html.

## Quality Assurance Methods

This study was conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations, Title 21, of the United States Code of Federal Regulations Part 58.^71^ In addition, this study was audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Developmental and Reproductive Toxicity Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.