# Introduction

Figure 1

2-Ethylhexyl p-Methoxycinnamate (CASRN 5466-77-3; Chemical Formula: C_18_H_26_O_3_; Molecular Weight: 290.40)

Synonyms: octinoxate; ethylhexyl methoxycinnamate; octyl methoxycinnamate; 2-propenoic acid, 3-(4-methoxyphenyl)-, 2-ethylhexyl ester; 2-ethylhexyl 3-(4-methoxyphenyl)prop-2-enoate.

Image generated with ChemSpider.^1^

## Chemical and Physical Properties

2-Ethylhexyl p-methoxycinnamate (EHMC; CASRN 5466-77-3) is a mixture of cis- and trans-isomers, with the trans-isomer (CASRN 83834-59-7) predominating. EHMC, also called octinoxate or octyl methoxycinnamate, is a colorless to light-yellow viscous liquid that is relatively insoluble in water (0.04 mg/L at 24ºC, pH 7.1) and is readily soluble in most organic solvents.^2,3^ EHMC absorbs ultraviolet (UV) A (320–400 nm) and UVB (290–320 nm) light and is photostable.^4,5^

## Production, Use, and Human Exposure

EHMC is synthesized by an insertion reaction of ketene with p-methoxybenzaldehyde or from enzymatic esterification of methoxycinnamic acid.^6,7^

EHMC at concentrations ≤7.5% is used in sunscreens and other personal care products to protect the wearer from solar erythema (21 CFR § 352.10). Per the Environmental Working Group’s Skin Deep^®^ Database,^8^ EHMC is found in approximately 750 sunscreens, lip balms, and moisturizers. EHMC (or its metabolites) has been detected in amounts as high as 19 ng/mL in human urine.^9^

## Regulatory Status

The U.S. Food and Drug Administration has approved use of up to 7.5% (w/w) EHMC in sunscreen, either alone or in combination formulations. Section 8(a) of the Toxic Substances Control Act requires manufacturers of this chemical to report preliminary assessment information concerned with production, exposure, and use to the U.S. Environmental Protection Agency.^10^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Absorption, distribution, metabolism, and excretion (ADME) data for EHMC in animals are limited. The National Toxicology Program (NTP) investigated the ADME of EHMC in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice after single gavage administration (8, 80, or 800 mg EHMC/kg body weight [mg/kg]), intravenous administration (8 mg/kg), or dermal application (0.8, 8, or 80 mg/kg, representing, respectively, 0.1%, 1%, or 10% of the formulation concentration) of [^14^C]EHMC.^11^ After gavage administration in male (8, 80, or 800 mg/kg) and female (8 mg/kg) rats, [^14^C]EHMC was highly absorbed (≥78%) and excreted mainly in urine (76%–82%), with approximately 2%–8% excreted in feces and approximately 1%–7% excreted as expired carbon dioxide (CO_2_) by 72 hours following administration. Very little (<1%) of the administered dose remained in tissues.

After a single gavage administration of 8 mg/kg [^14^C]EHMC in male and female mice, 57%–73%, 15%–25%, and 2%–3% of the administered dose was recovered by 72 hours postadministration in urine, feces, and as exhaled CO_2_, respectively. While the pattern of disposition of EHMC in mice was similar to that in rats, the higher amount of the dose recovered in feces in mice compared to rats is likely due to contamination of feces with urine as has been observed in other mice disposition studies. The disposition of [^14^C]EHMC after intravenous administration was similar to that following gavage administration.^11^

Absorption of [^14^C]EHMC was high after a single dermal application, using ethanol or acetone as a vehicle, to a covered dose site. In male and female rats after a single application of 8 mg/kg [^14^C]EHMC, approximately 34%–42% of the applied dose was absorbed. In male (0.8, 8, or 80 mg/kg) and female (8 mg/kg) mice following a single dermal application of [^14^C]EHMC, approximately 36%–62% of the applied dose was absorbed. Using a lotion vehicle (olive oil:emulsifying wax:water 15:15:70 [v/w/v]), most of the applied dose was unabsorbed in rats; only 11% of the dose was absorbed with approximately 4% remaining at the dose site skin. The pattern of disposition and metabolism of [^14^C]EHMC following dermal application in rats and mice was similar to that after gavage administration.^11^

Numerous metabolites were detected in urine, including the purported developmental toxicants 2-ethylhexanol and 2-ethylhexanoic acid (Figure 2); parent EHMC was not detected under the conditions used in these assessments.^11^ Huang et al.^9^ also reported five metabolites of EHMC in urine and plasma following single gavage administration of 200 or 1,000 mg/kg EHMC in male Sprague Dawley rats. EHMC was cleared rapidly in rat and mouse hepatocytes with estimated half-lives of ≤3 minutes.^11^

Figure 2

Metabolism of 2-Ethylhexyl p-Methoxycinnamate in Rodents

(1) 2-Ethylhexyl p-methoxycinnamate; (2) p-methoxycinnamate; (3) p-methoxycinnamate glucuronide; (4) p-methoxycinnamate glycine; (5) hydroxycinnamate sulfate; (6) hydroxycinnamate glycine; (7) hydroxy methoxycinnamate; (8) hydroxy methoxycinnamate sulfate; (9) ethylhexanol; (10) ethylhexanol glucuronide; (11) 2-ethylhexanoic acid; (12) 2-ethylhexanoic acid glucuronide; (13) 2-ethyl-5-ketohexanoic acid glucuronide; (14) 2-ethyladipate; (15) ethyladipate glucuronide; (16) hydroxyethylhexanoic acid glucuronide.^11^

### Humans

Following a whole-body application of 2 mg/cm^2^ of basic cream formulation containing 10% w/w EHMC to 32 human volunteers, EHMC was detected in plasma and urine.^12^ Several in vitro investigations of dermal absorption of EHMC in isolated skin preparations have reported uptake of EHMC.^13,14^ Klimová et al.^15^ estimated systemic human exposures of up to 1,032 μg/kg/day from in vitro uptake studies of oil-water EHMC sunscreen emulsion applications to pig-ear skin. In another in vitro study investigating the absorption of EHMC through pig skin, considerably greater amounts of the dose were absorbed when EHMC was applied in an emulsion rather than when the material was applied in a microencapsulated formulation.^16^ EHMC absorption was approximately 50% lower after in vitro application to human skin encapsulated in solid lipid nanoparticles than after application in an oil-water emulsion.^17^ A study of children aged 6 to 18 from a suburban district of Shanghai identified EHMC, 4-methoxycinnamic acid, and 4-methoxyacetophenone present in urine at approximately 19, 41, and 27 ng/mL, respectively.^9^ EHMC was cleared in human hepatocytes more slowly than in rodents with an estimated half-life of ≤48 minutes.^11^

## Developmental and Reproductive Toxicity

### Models of Endocrine Activity

EHMC has been reported to have weak in vitro estrogenic activity, to induce estrogen receptor (ER) transactivation, and to stimulate ER-dependent MCF-7 cell proliferation (median effective concentration [EC_50_] = 2.37 μM).^18-20^ Schlumpf et al.^18^ reported that EHMC induced a uterotrophic response in immature rats (median effective dose [ED_50_] = 934 mg/kg/day). Other investigators observed uterotrophy in ovariectomized adult rats administered 1 g/kg, along with “estrogen” consistent increases in uterine C3, pituitary truncated estrogen receptor product-1 (TERP-1), and liver insulin-like growth factor 1 (IGF1) expression.^21^ EHMC did not repress androgen receptor (AR)-mediated transition in AR CALUX^®^ (Chemically Activated LUciferase eXpression) cells, but resulted in repression of transcription of human progesterone receptor (PR) in PR CALUX cells (median inhibition concentration [IC_50_] = 0.5 μM).^20^

### Experimental Animals

Some animal studies suggest possible effects on reproduction. F_1_ male Wistar Han rats exposed perinatally to EHMC displayed lower sperm counts and lower ventral prostate weights than control males.^22^ In a two-generation dietary study (0, 150, 450, or 1,000 mg/kg/day), after a 14-week premating period, no EHMC-related effects on mating performance or fertility were observed. F_0_ and F_1_ female Wistar rats exposed to 1,000 mg/kg/day displayed reductions in the numbers of implantation sites and apparent litter size, which were attributed to maternal toxicity.^23^ F_1_-exposed males displayed a slight reduction in cauda sperm concentration. EHMC exposure was associated with lower postnatal body weight gain in pups. F_1_ and F_2_ generations exposed to 1,000 mg/kg/day displayed delays in vaginal opening, balanopreputial separation, and lower body weights on day of attainment.^23,24^

Limited data do not suggest developmental abnormalities in experimental animals exposed to EHMC. In a guideline rabbit study (stock not defined), does administered EHMC at 0, 80, 200, or 500 mg/kg/day by gavage during fetal organogenesis (days not defined; dose level justification not presented) exhibited a slight decrease in maternal weight. Fetal weight was only slightly lower in the 500 mg/kg/day group, and “no fetal abnormalities” were reported (details limited).^25^ In a guideline rat study (strain not defined), mated rats were administered 0–1,000 mg/kg/day EHMC from gestation days (GDs) 6–14, consistent with a pilot study (presumed gavage), and a subset was allowed to litter and rear their offspring. The percentage of resorptions in the 1,000 mg/kg/day dose group was higher than in all other groups but was attributed to unexpected low numbers of resorptions observed in those groups. No other findings were noted.^25^

#### Endocrine Disruptor Screening Panel Studies

NTP sponsored mammalian Endocrine Disruptor Screening Panel (EDSP) Tier 1 studies^26^ in which EHMC at maximal feasible doses did not interact with ER isolated from rat uteri (100 μM), induce ER transcriptional activation in HeLa-9903 cells (0.01 μM), or induce a uterotrophic response (1 g/kg) in young ovariectomized Sprague Dawley Crl:CD^®^ IGS rats. EHMC at maximal feasible doses was categorized as a nonbinder of AR isolated from rat prostate (100 μM), did not induce transcriptional activation, and had no apparent inhibitory effect on dihydrotestosterone-induced AR transcriptional activity in MDA-kb2 cells (32 μM). In the Hershberger assay, EHMC (1 g/kg) had no effect on androgen-dependent organ weights in the absence of androgenic action. In the presence of testosterone propionate, EHMC did not attenuate the expected androgen-mediated increase in organ weights, demonstrating that EHMC does not exhibit antiandrogenic activity in vivo at the doses assessed. EHMC was classified as a noninhibitor of aromatase activity (100 μM) and was negative in the H295R human adrenocarcinoma cell steroidogenesis assay at the highest concentration that could be evaluated (0.1 μM).^26^

### Humans

In a study using human sperm, EHMC was shown to induce Ca^2+^ signaling (EC_50_ = 1.9 μM), which is normally associated with the progesterone-induced acrosomal reaction via the Catsper channel (sperm-specific, Ca^2+^-permeable, pH-sensitive, and weakly voltage-dependent ion channel). The signal was not sufficient to significantly induce the acrosomal reaction or to affect sperm penetration or viability.^27,28^

## General Toxicity

### Experimental Animals

Acute and subchronic toxicity appears to be low. The acute oral median lethal dose (LD_50_) of EHMC is >8 g/kg for mice and >5 g/kg for rats.^29^ In a 13-week study using Füllinsdorf Albino SPF rats (with recovery group) at dietary concentrations of 0, 200, 450, or 1,000 mg/kg/day, the 1,000 mg/kg/day group displayed a transient increase in kidney weight, which was attributed to the physiological response to increased EHMC eliminatory activity.^25^ This exposed group also displayed lower glycogen levels and a higher iron concentration in Kupfer cells. Two animals in this exposed group exhibited minimal centrilobular necrosis with infiltration (a finding also observed in control rats but with less severity). High-exposure concentration females exhibited transiently increased glutamate dehydrogenase levels. The no-observed-adverse-effect level (NOAEL) was established at 450 mg/kg/day. A 13-week dermal study in Sprague Dawley rats at doses up to 555 mg/kg/day did not reveal any adverse responses, other than an increase in liver weight at the highest dose without concurrent adverse histopathological findings. The sponsor suggested the NOAEL to be 555 mg/kg but given the effect on liver weight observed at this dose, the European Commission’s Scientific Committee on Cosmetology rationalized the NOAEL as the next lower dose (227 mg/kg/day).^25^

### Humans

The literature contains no studies on the general toxicity of EHMC in humans.

## Immunotoxicity

### Experimental Animals

Limited available data do not indicate immunotoxicity of EHMC. EHMC did not induce irritation upon instillation in the rabbit conjunctival sac^30^ or after topical application on guinea pigs for 16 days.^31^ When EHMC was applied daily for 16 days to guinea pigs, and the animals were challenged 3 days after the last application, there were no signs of sensitization.^25^

### Humans

Studies examining the potential for EHMC to induce allergic contact dermatitis are limited. When patients that previously presented with an eczematous reaction in areas likely exposed to sunlight were subjected to photopatch tests using a standard series of sunscreens, EHMC induced a low relative photoallergenic response (1/26 positives; 1/82 subjects) and did not induce contact dermatitis.^32^ These findings are consistent with a study conducted in Singapore^33^ and a retrospective analysis of photoallergic and allergic contact results from patients using one of 11 UV filters.^34^

Topical application of EHMC for 24 and 48 hours was not associated with irritation of the skin.^25^ A Draize repeated insult patch with a 2% formulation of EHMC (vehicle not stated) did not result in sensitization. A formulation of 7.5% EHMC in petroleum jelly that was topically applied and occluded for 48 hours and repeated 11 times, followed by a challenge application 14 days after the last application, was not associated with any adverse reactions. Similar results were observed with a 10% formulation of EHMC in dimethylphthalate.^25^

## Study Rationale

EHMC was nominated by the National Cancer Institute and recommended for comprehensive toxicological characterization, including carcinogenicity and developmental toxicity studies, and for characterization of photodecomposition products. The nomination was based on EHMC’s extensive use, widespread consumer exposure in sunscreens, and reported estrogenic and reproductive effects. This study is part of a larger NTP effort examining whether UV filters are associated with toxicity in in vitro and in vivo models that inform potential human hazard.^35^ Given the purported effects on hormonally responsive endpoints, NTP characterized the estrogenic, androgenic, and antiandrogenic potential of EHMC in in vitro and short-term in vivo EDSP studies.^26^ To characterize potential EHMC-induced effects on fertility, fecundity, and subchronic toxicity, the toxicological potential of EHMC was assessed in the rat modified one-generation study design. This design was chosen to increase the likelihood of identifying adverse responses over interrelated endpoints. The design includes assessment of F_1_ general toxicity and histological examinations that could identify early proliferative lesions.