# Appendix E Supplemental Data

The following supplemental files are available at: h[underlined: ttps://doi.org/10.22427/NTP-DATA-DART-06][underlined: .]

## E.1 Dose Range-finding Study – Rats

### E.1.1 Data Tables

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I05P – Pup Clinical Observations Summary

I06 – Mean Feed Consumption

I08 – Mean Test Compound Consumption

R01 – Multigeneration Cross Reference

R02 – Reproductive Performance Summary

R03 – Summary of Litter Data

R19 – Pup Mean Body Weight Summary

R19C – Pup Growth Curves

R19G – Pup Mean Body Weight Gain

R20 – Pup Necropsy Summary

### E.1.2 Individual Animal Data

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Gross Pathology Data

Individual Animal Litter Data

Individual Animal Pup Body Weight Data

Individual Animal Pup Clinical Observations Data

Individual Animal Pup Necropsy Data

Individual Animal Removal Reasons Data

Individual Animal Reproductive Performance Data

## E.2 Modified One-Generation Study – Rats

### E.2.1 Data Tables

F1 All Cohorts Vaginal Cytology Plots

F1 All Cohorts Vaginal Cytology Summary

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I05P – Pup Clinical Observations Summary

I06 – Mean Feed Consumption

I08 – Mean Test Compound Consumption

PA02R – Neoplastic Lesion Summary with Percent and Litter Incidence

PA03R – Non-Neoplastic Lesion Summary with Percent and Litter Incidence

PA05R – Incidence Rates of Neoplastic Lesions with Litter Incidence Systemic Lesions Abridged

PA06R – Organ Weights Summary

PA08R – Statistical Analysis of Neoplastic Lesions with Litter Incidence

PA10R – Statistical Analysis of Non-Neoplastic Lesions with Litter Incidence

PA11 – Statistical Analysis of Survival Data

PA14 – Individual Animal Pathology Data

PA18R – Non-Neoplastic Lesion Summary with Mean Severity Grade and Litter Incidence

PA40 – Survival Curve

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

PA46R – Summary of Gross Pathology with Litter Incidence

R01 – Multigeneration Cross Reference

R02 – Reproductive Performance Summary

R03 – Summary of Litter Data

R04 – Anogenital Distance Summary

R06 – Andrology Summary

R09 – Uterine Content Summary

R10 – Fetal Defects

R11 – Fetal Defect Summary

R13 – Fetal Defect Cross Reference Summary

R14 – Developmental Markers Summary

R14C – Time to Attainment Curves for Testicular Descent

R16 – Pubertal Markers Summary

R16C – Time to Attainment Curves for Pubertal Markers

R19 – Pup Mean Body Weight Summary

R19C – Pup Growth Curve

R19G – Pup Mean Body Weight Gain

R20 – Pup Necropsy Summary

Vaginal Cytology Markov Model

### E.2.2 Individual Animal Data

F1 Fertility Cohort Vaginal Cytology Plots

F1 Prechronic Cohort Vaginal Cytology Plots

F1 Prenatal Cohort Vaginal Cytology Plots

Individual Animal Andrology Data

Individual Animal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Developmental Markers Data

Individual Animal Gross Pathology Data

Individual Animal Hematology Data

Individual Animal Histopathology Data

Individual Animal Litter Data

Individual Animal Organ Weight Data

Individual Animal Pup Body Weight Data

Individual Animal Pup Clinical Observations Data

Individual Animal Pup Necropsy Data

Individual Animal Removal Reasons Data

Individual Animal Reproductive Performance Data

Individual Animal Teratology Dam Data

Individual Animal Teratology Fetal Weight Data

Individual Animal Teratology Implant Findings Data