# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that could affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals are from the same production source and weanling groups as the animals used for the studies of test compounds.

For these dose range-finding and modified one-generation studies, blood samples were collected from each sentinel animal and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately with serology and Helicobacter testing was performed by IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens. Evaluation for endo- and ectoparasites was performed in-house by the testing laboratory.

The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed (Table C-1).

## C.2 Results

All test results were negative.

Table C-1 Methods and Results for Sentinel Animal Testing in Male and Female Rats

Collection Time Points | Dose Range-finding Study | | Modified One-Generation Study
Collection Time Points | Quarantine | Study Termination | Quarantine | 1 Month After Arrival | 16 Weeks After Arrival | 12 Weeks After Birth^a^ | 22 Weeks After Birth^a^ | Study Termination
Number Examined (Males/Females)^b^ | 0/5 | 0/5 | 0/5 | 0/5 | 0/5 | 5/0 | 5/0 | 0/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | − | − | − | − | − | − | − | −
Mycoplasma pulmonis | − | − | − | − | − | − | − | −
Parvo NS-1 | − | − | − | − | − | − | − | −
Pneumonia virus of mice (PVM) | − | − | − | − | − | − | − | −
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | − | − | − | − | − | − | − | −
Rat minute virus (RMV) | − | − | − | − | − | − | − | −
Rat parvo virus (RPV) | − | − | − | − | − | − | − | −
Rat theilovirus (RTV) | − | − | − | − | − | − | − | −
Sendai | − | − | − | − | − | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | − | − | − | − | − | − | − | −
Toolan’s H-1 | − | − | − | − | − | − | − | −
Immunofluorescence Assay (IFA)
Mycoplasma pulmonis | NT | NT | NT | − | NT | NT | NT | NT
Pneumocystis carinii | − | NT | − | NT | NT | NT | NT | NT
Pneumonia virus of mice (PVM) | NT | NT | NT | NT | NT | NT | NT | −
Polymerase Chain Reaction (PCR)
Helicobacter species | NT | NT | NT | NT | − | − | − | −

− = negative; + = positive; NT = not tested.

^a^ Male rats born at RTI.

^b^ Age-matched nonpregnant females.