# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in 5K96 Rat Ration

Additional information on ingredients, vitamins, and minerals in the 5K96 rat diet can be found online.^79^

Table B-1 Nutrient Composition of 5K96 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 21.3 ± 0.6797 | 20.6–22.3 | 5
Crude Fat (% by Weight) | 4.38 ± 0.0837 | 4.3–4.5 | 5
Crude Fiber (% by Weight) | 3.174 ± 0.1932 | 2.9–3.43 | 5
Ash (% by Weight) | 6.11 ± 0.2519 | 5.71–6.41 | 5
Vitamins
Vitamin A (IU/kg) | 18,920 ± 2,509 | 14,600–20,800 | 5
Thiamine (ppm)^a^ | 17.24 ± 1.718 | 15–19 | 5
Minerals
Calcium (%) | 1.228 ± 0.0497 | 1.16–1.29 | 5
Phosphorus (%) | 0.930 ± 0.0227 | 0.901–0.955 | 5

^a^ As hydrochloride.

Table B-2 Contaminant Levels in 5K96 Rat Ration

Contaminant | Mean ± Standard Deviation | Range | Number of Samples
Arsenic (ppm) | 0.3484 ± 0.0327 | 0.316–0.391 | 5
Cadmium (ppm) | 0.0384 ± 0.0052 | 0.0328–0.0435 | 5
Lead (ppm) | 0.2264 ± 0.0152 | 0.215–0.251 | 5
Mercury (ppm) | 0.0104 ± 0.0006 | 0.01–0.0113 | 5
Selenium (ppm) | 0.355 ± 0.0226 | 0.338–0.392 | 5
Aflatoxins (ppb)^a^ | <2.0 | – | 5
Nitrate Nitrogen (ppm)^b^ | 13.14 ± 2.7428 | 10.4–17.1 | 5
Nitrite Nitrogen (ppm)^a,b^ | <1.0 | – | 5
BHA (ppm)^a,c^ | <1.0 | – | 5
BHT (ppm)^a,c^ | <1.0 | – | 5
Aerobic Plate Count (CFU/g)^d^ | <10 | – | 5
Coliform (MPN/g) | <3.0 | – | 5
Escherichia coli (MPN/g)^a^ | <10.0 | – | 5
Salmonella (MPN/g) | <3.0 | – | 5
Total Nitrosamines (ppb)^e^ | 5.6 ± 2.5 | 2.0–8.4 | 5
N-N-dimethylamine (ppb)^e^ | 4.1 ± 1.8 | 2.0–6.3 | 5
N-N-pyrrolidine (ppb)^e^ | 1.5 ± 0.9 | 0.0–2.4 | 5
Pesticides (ppm)
α-BHC^a^ | – | – | 5
β-BHC^a^ | – | – | 5
γ-BHC^a^ | – | – | 5
δ-BHC^a^ | – | – | 5
Heptachlor^a^ | – | – | 5
Aldrin^a^ | – | – | 5
Heptachlor Epoxide^a^ | – | – | 5
DDE^a^ | – | – | 5
DDD^a^ | – | – | 5
DDT^a^ | – | – | 5
HCB^a^ | – | – | 5
Mirex^a^ | – | – | 5
Methoxychlor^a^ | – | – | 5
Dieldrin^a^ | – | – | 5
Endrin^a^ | – | – | 5
Telodrin^a^ | – | – | 5
Chlordane^a^ | – | – | 5
Toxaphene^a^ | – | – | 5
Estimated PCBs^a^ | – | – | 5
Ronnel^a^ | – | – | 5
Ethion^a^ | – | – | 5
Trithion^a^ | – | – | 5
Diazinon^a^ | – | – | 5
Methyl Chlorpyrifos | 0.056 ± 0.0601 | 0–0.136 | 5
Methyl Parathion^a^ | – | – | 5
Ethyl Parathion^a^ | – | – | 5
Malathion | 0.016 ± 0.0089 | 0–0.02 | 5
Endosulfan I^a^ | – | – | 5
Endosulfan II^a^ | – | – | 5
Endosulfane Sulfate^a^ | – | – | 5

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ Preirradiation values given.

^e^ All values were corrected for percent recovery.