# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

2-Ethylhexyl p-methoxycinnamate (EHMC) was obtained from Acros Organics (Fair Lawn, NJ) in a single lot (A0293319). Identity, purity, and stability analyses were conducted by the analytical chemistry lab at MRIGlobal (Kansas City, MO). Reports on analyses performed in support of the EHMC study are on file at the National Institute of Environmental Health Sciences.

EHMC is a clear, colorless liquid. The identity of lot A0293319 was evaluated using Fourier Transform infrared (FT-IR) spectroscopy, ^1^H nuclear magnetic resonance (NMR) spectroscopy, ^13^C NMR spectroscopy, and gas chromatography (GC) with mass spectrometry (MS) (Table A-1).

The FT-IR, ^1^H NMR, and ^13^C NMR spectra (Figure A-1, Figure A-2, Figure A-3) were consistent with the structure of EHMC and reference spectra for the trans-isomer in the National Institute of Advanced Industrial Science and Technology Spectral Database (No. 19199). The GC/MS spectra corresponded with the National Institute of Standards and Technology Mass Spectral Library reference for EHMC.

Elemental analysis was conducted at Prevalere Life Science, Inc. (Whitesboro, NY) and found to be consistent with the composition of EHMC. The relative amount of carbon (74.50%), hydrogen (9.16%), and nitrogen (0.06%) in lot A0293319 were within 2% of anticipated ratios. Karl Fisher titration indicated a water content of <0.1%. Triplicate analysis of the boiling point of lot A0293319 indicated a boiling point of 250.5°C–275.1°C at 30 inHg. The relative density of 1.012 at 21.5°C agreed with anticipated specific gravity of 1.007–1.012 at 25°C indicated by the supplier. The log P_ow_ value determined was 5.27.

The purity of lot A0293319 was determined using GC with flame ionization detection (FID) conducted with two different column types. The GC/FID analysis conducted with a DB-5 column (Table A-1, System B) indicated a purity of 99.17%. Similarly, the GC/FID analysis using a Rtx-200 column (Table A-1, System C) determined a purity of 98.99%. Both methods identified three impurities having an area ≥0.05%. The purity of lot A0293319 was determined to be >98%.

Accelerated stability studies were conducted on samples stored protected from light at ambient (approximately 22°C), refrigerated (approximately 5°C), elevated (approximately 60°C), and frozen (approximately −20°C) temperatures using GC/FID (Table A-1). Stability was confirmed for at least 2 weeks under these conditions. Upon receipt by the analytical laboratory, the 150 kg drum of lot A0293319 was homogenized by blending all portions of the drum with an air-driven stirrer. The chemical was then transferred to 1-gallon narrow-mouthed amber glass bottles sealed with Teflon-lined lids. Periodic reanalysis of the bulk chemical performed during and after the studies showed no degradation.

## A.2 Preparation and Analysis of Dose Formulations

Dose formulations of EHMC in LabDiet 5K96 Verified Casein Diet 10 IF feed were prepared following the protocols outlined in Table A-2. Dose formulations of 1,000, 3,000, and 6,000 ppm were used for the modified one-generation study. Formulations were stored at approximately 5°C and were considered stable for 35 days.

Dose formulations and homogeneity were evaluated using GC/FID (Table A-1, System D). The method of preparation was validated for concentration ranges of 400–25,000 ppm, as well as high-dose formulations of 40,000 and 80,000 ppm used as stock feed. Homogeneity was confirmed in 22 kg preparations of dose formulations at 1,000, 2,250, and 20,000 ppm.

Prior to study start, the stability and homogeneity of the dose formulations were determined using GC/FID. Stability of the 1,000 ppm formulation was confirmed for 35 days at refrigerated temperatures (5°C). A 7-day simulated dose study of the 1,000 ppm formulations was conducted to determine stability in animal room conditions. Isolated formulations and formulations mixed with 5% w/w rodent urine and feces reflective of anticipated conditions were stable for <4 days at a concentration of 1,000 ppm.

Analyses of preadministration and postadministration dose formulations were conducted throughout the study by the study laboratory, RTI International (Research Triangle Park, NC). Postadministration samples were collected from the animal room at the end of the first exposure period. All samples were within 10% of the target concentration with the exception of three postadministration formulations from the dose range-finding study (Table A-3, Table A-4). One batch of the 6,000 ppm dose formulation prepared on December 3, 2012, was 9.2% below the target concentration and was subsequently replaced by a freshly prepared batch (9.0% below target).

Table A-1 Chromatography Systems Used in the Modified One-Generation Study of 2-Ethylhexyl p-Methoxycinnamate

Chromatography | Detection System | Column | Mobile Phase
System A
Gas chromatography | Mass spectrometer | HP-5MS (30 m × 0.25 mm ID, 0.25 µm film thickness) | Helium, 1.5 mL/min flow rate
System B
Gas chromatography | Flame ionization detector | J&W Scientific DB-5 (30 m × 0.53 mm ID, 1.5 µm film thickness) | Helium, 10 mL/min flow rate
System C
Gas chromatography | Flame ionization detector | Restek, Rtx-200 (30 m × 0.25 mm ID, 0.25 µm film thickness) | Helium, 2.5 mL/min flow rate
System D
Gas chromatography | Flame ionization detector | Agilent DB-5 (30 m × 0.53 mm ID, 1.5 µm film thickness) | Helium, 10 mL/min flow rate

ID = internal diameter.

Table A-2 Preparation and Storage of Dose Formulations in the Modified One-Generation Study of 2-Ethylhexyl p-Methoxycinnamate

Preparation
A premix of 2-ethylhexyl p-methoxycinnamate (EHMC) (Lot A0293319) and LabDiet 5K96 Verified Casein Diet 10 IF feed was diluted with additional feed to reach the target concentration. To make the premix, an appropriate amount of LabDiet 5K96 Verified Casein Diet 10 IF feed was weighed into a plastic bag. A small portion was transferred from the bag into a stainless-steel container and a well was shaped in the middle of the feed (feed well). An appropriate amount of EHMC was weighed into a stainless-steel beaker and poured into the feed well. The contents were mixed thoroughly with a spatula. The remaining feed was used to wash residual EHMC from the weighing container and sides of the stainless-steel mixing container. The contents were mixed thoroughly using the spatula between additions until all feed was incorporated into the premix. To prepare the formulations from the premix, feed was weighed into a plastic bag. Feed was transferred to an 8-quart twin shell blender and evenly distributed into each. An appropriate amount of premix was added to the blender and also evenly distributed between ports. The remaining feed was used to rinse the premix container into the blender. The blender ports were sealed, and the formulation was blended for approximately 15 minutes using an intensifier bar for the first 5 minutes.
Chemical Lot Number
A0293319 (Acros Organics)
Maximum Storage Time
35 days
Storage Conditions
Polyethylene bags stored at 5°C (refrigerated)
Study Laboratory
RTI International (Research Triangle Park, NC)

Table A-3 Results of Analyses of Dose Formulations Administered to Rats in the Dose Range-finding Study of 2-Ethylhexyl p-Methoxycinnamate

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
February 1, 2012 | February 6–8, 2012 | 0 | BLOQ | NA
February 1, 2012 | February 6–8, 2012 | 2,250 | 2,170 | −3.6
February 1, 2012 | February 6–8, 2012 | 5,000 | 4,910 | −1.8
February 1, 2012 | February 6–8, 2012 | 10,000 | 9,900 | −1.0
February 1, 2012 | February 6–8, 2012 | 20,000 | 20,500 | 2.5
March 15, 2012 | March 12–20, 2012 | 0 | BLOQ | NA
March 15, 2012 | March 12–20, 2012 | 2,250 | 2,190 | −2.7
March 15, 2012 | March 12–20, 2012 | 5,000 | 4,880 | −2.4
March 15, 2012 | March 12–20, 2012 | 10,000 | 9,690 | −3.1
March 15, 2012 | March 12–20, 2012 | 20,000 | 19,200 | −4.0
Animal Room Samples
February 1, 2012 | March 12–13, 2012 | 0 | BLOQ | NA
February 1, 2012 | March 12–13, 2012 | 2,250 | 2,020 | −10.2
February 1, 2012 | March 12–13, 2012 | 5,000 | 4,540 | −9.2
February 1, 2012 | March 12–13, 2012 | 10,000 | 9,080 | −9.2
February 1, 2012 | March 12–13, 2012 | 20,000 | 18,000 | −10.0
March 15, 2012 | April 10–12, 2012 | 0 | BLOQ | NA
March 15, 2012 | April 10–12, 2012 | 2,250 | 1,980 | −12.0
March 15, 2012 | April 10–12, 2012 | 5,000 | 4,420 | −11.6
March 15, 2012 | April 10–12, 2012 | 10,000 | 9,300 | −7.0

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analysis.

Table A-4 Results of Analyses of Dose Formulations Administered to Rats in the Modified One-Generation Study of 2-Ethylhexyl p-Methoxycinnamate

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
September 17, 2012 | September 20, 2012 | 0 | BLOQ | NA
September 17, 2012 | September 20, 2012 | 1,000 | 953 | −4.7
September 17, 2012 | September 20, 2012 | 3,000 | 2,840 | −5.3
September 17, 2012 | September 20, 2012 | 6,000 | 5,710 | −4.8
December 3, 2012 | December 5–7, 2012 | 0 | BLOQ | NA
December 3, 2012 | December 5–7, 2012 | 1,000 | 981 | −1.9
December 3, 2012 | December 5–7, 2012 | 1,000 | 979 | −2.1
December 3, 2012 | December 5–7, 2012 | 3,000 | 2,870 | −4.3
December 3, 2012 | December 5–7, 2012 | 3,000 | 2,900 | −3.3
December 3, 2012 | December 5–7, 2012 | 6,000 | 5,820 | −3.0
December 3, 2012 | December 5–7, 2012 | 6,000 | 5,450 | −9.2^b^
December 11, 2012 | December 11, 2012 | 6,000 | 5,460 | −9.0
January 14, 2013 | January 16–17, 2013 | 0 | BLOQ | NA
January 14, 2013 | January 16–17, 2013 | 1,000 | 964 | −3.6
January 14, 2013 | January 16–17, 2013 | 3,000 | 3,010 | +0.3
January 14, 2013 | January 16–17, 2013 | 6,000 | 6,150 | +2.5
February 18, 2013 | February 21–22, 2013 | 0 | BLOQ | NA
February 18, 2013 | February 21–22, 2013 | 1,000 | 957 | −4.3
February 18, 2013 | February 21–22, 2013 | 3,000 | 2,810 | −6.3
February 18, 2013 | February 21–22, 2013 | 6,000 | 5,700 | −5.0
Animal Room Samples
September 17, 2012 | November 7–8, 2012 | 0 | BLOQ | NA
September 17, 2012 | November 7–8, 2012 | 1,000 | 907 | −9.3
September 17, 2012 | November 7–8, 2012 | 3,000 | 2,740 | −8.7
September 17, 2012 | November 7–8, 2012 | 6,000 | 5,440 | −9.3

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Average of triplicate analysis.

^b^ The formulation was not used in the study and was replaced by the formulation prepared on December 11, 2012.

Figure A-1

Fourier Transform Infrared Absorption Spectrum of 2-Ethylhexyl p-Methoxycinnamate (Lot A0293319)

Figure A-2

Fourier Transform ^1^H Nuclear Magnetic Resonance Spectrum of Reference Sample of 2-Ethylhexyl p-Methoxycinnamate (Lot A0293319)

Figure A-3

Fourier Transform ^13^C Nuclear Magnetic Resonance Spectrum of 2-Ethylhexyl p-Methoxycinnamate (Lot A0293319)