# Overview

The National Toxicology Program (NTP) has assessed the potential adverse effects of sunscreens using in vitro and in vivo model systems; the data presented herein are part of that larger effort. The scope of 2-hydroxy-4-methoxybenzophenone (2H4MBP) studies includes the assessment of potential endocrine activity as outlined in the U.S. Environmental Protection Agency Endocrine Disruptor Screening Program Tier 1 studies (estrogen- and androgen-receptor binding and activation, Hershberger and uterotrophic assays, aromatase inhibition, and steroid synthesis inhibition) and characterization of the potential effects of continuous 2H4MBP exposure over multiple generations using the NTP modified one-generation study design. In this study, exposure to 2H4MBP in feed began on gestation day (GD) 6. At weaning, 1 and 2 pups/sex/litter were allocated to prenatal and reproductive performance cohorts, respectively; an additional 1 pup/sex/litter was allocated to the biological sampling cohort. In addition to an assessment of reproductive performance, F_2_ fetal outcomes (GD 21 fetal examinations) were assessed in the prenatal cohort and the potential effects on parturition and early growth of the F_2_ generation were assessed in the reproductive performance cohort. Internal dose metrics were also assessed. Apical indicators sensitive to endocrine modulation were measured. The U.S. Food and Drug Administration’s National Center for Toxicological Research (NCTR), in partnership under an Interagency Agreement, has also examined the effects of maternal and lactational exposure to 2H4MBP on development and reproductive organs in male and female rat offspring and on transcriptional changes in the testes and prostates of young rats. NCTR is also conducting fertility, embryo-fetal, and pre- and postnatal rat studies to characterize the potential effects of 2H4MBP exposure. This report complements the International Council for Harmonisation of Technical Requirements for Pharmaceuticals for Human Use (ICH) S5r2 guideline studies on 2H4MBP conducted by NCTR and allows for the comparison of study designs and outcomes. NTP previously conducted rat and mouse 2- and 13-week toxicity studies by dermal and oral routes of exposure and assessed the genotoxic potential of 2H4MBP. Potential effects of 2H4MBP exposure on mouse reproduction were assessed using the Reproductive Assessment by Continuous Breeding protocol. NTP has also conducted 2-year toxicology and carcinogenesis studies in rats (including perinatal exposure) and mice using dietary exposure.