# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2690-2052

DOI: https://doi.org/10.22427/NTP-DART-05

Report Series: NTP Developmental and Reproductive Toxicity Report Series

Report Series Number: 05

Official citation: National Toxicology Program (NTP). 2022. NTP developmental and reproductive toxicity technical report on the modified one-generation study of 2-hydroxy-4-methoxybenzophenone (CASRN 131-57-7) administered in feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats with prenatal and reproductive performance assessments in F_1_ offspring. Research Triangle Park, NC: National Toxicology Program. DART Report 05.