# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  B.S. McIntyre, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  H.C. Cunny, Ph.D.
  P.M. Foster, Ph.D. (Retired)
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D. (Retired)
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  G.K. Roberts, Ph.D.
  V.G. Robinson, M.S.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  M.D. Stout, Ph.D.
  V.L. Sutherland, Ph.D.
  M.K. Vallant, M.S. (Retired)
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- Provided pathology review
  J.C. Seely, D.V.M., Principal Investigator
  C.C. Shackelford, D.V.M., Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Conducted studies and evaluated findings
  C.J. Price, Ph.D., Principal Investigator (Dose Range-finding Study)
  R.W. Tyl, Ph.D., Principal Investigator (Modified One-Generation Study)
  K.J. Turner, Ph.D.
- Battelle, Columbus, Ohio, USA
  Conducted prestart chemistry activities and dose formulations
  S.W. Graves, B.S., Principal Investigator
  T.A. Cristy, B.A.
  R.E. Haney, M.S.
  J.S. Richey, B.S.
- Social & Scientific Systems, a DLH Company, Research Triangle Park, North Carolina, USA
  Provided statistical analyses
  S. McBride, Ph.D., Principal Investigator
  L.J. Betz, M.S.
- Pathology Associates International, a Charles River Company, Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group on modified one-generation studies (March 1, 2016)
  C.L. Johnson, D.V.M.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  P. Brown, B.S.
  C. Myers, M.S.
  A. Raghuraman, M.S.
  N. Sayers, B.S.
  V. Youn, M.S.
- ICF, Fairfax, Virginia, USA
  Contributed to technical writing and data integration and ensured report quality
  S.J. Snow, Ph.D.