# References

1 Tarras-Wahlberg N, Rosén A, Stenhagen G, Larkö O, Wennberg A-M, Wennerström O. Changes in ultraviolet absorption of sunscreens after ultraviolet irradiation. J Invest Dermatol. 1999; 113(4):547–553. 10.1046/j.1523-1747.1999.00721.x 10504439
2 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 4632, Oxybenzone. 2022. https://pubchem.ncbi.nlm.nih.gov/compound/4632#section
3 Environmental Working Group (EWG). EWG’s guide to sunscreen. 2017. https://www.ewg.org/sunscreen/ [Accessed: July, 2017 ]
4 Yousif E, Haddad R. Photodegradation and photostabilization of polymers, especially polystyrene. Springerplus. 2013; 2(1):398. 10.1186/2193-1801-2-398 25674392
5 Christian M. Final report on the safety assessment of benzophenones-1,-3,-4,-5,-9, and-11. J Am Coll Toxicol. 1983;2(5):35–77.
6 Code of Federal Regulations (CFR). Title 21. 177:1010.
7 Wang L, Kannan K. Characteristic profiles of benzonphenone-3 and its derivatives in urine of children and adults from the United States and China. Environ Sci Technol. 2013; 47(21):12532–12538. 10.1021/es4032908 24073792
8 Han C, Lim Y-H, Hong Y-C. Ten-year trends in urinary concentrations of triclosan and benzophenone-3 in the general US population from 2003 to 2012. Environ Pollut. 2016;208:803–810. 10.1016/j.envpol.2015.11.002 26602792
9 Calafat AM, Wong L-Y, Ye X, Reidy JA, Needham LL. Concentrations of the sunscreen agent benzophenone-3 in residents of the United States: National Health and Nutrition Examination Survey 2003–2004. Environ Health Perspect. 2008; 116(7):893–897. 10.1289/ehp.11269 18629311
10 Code of Federal Regulations (CFR). Title 21. 352:21.
11 el Dareer SM, Kalin JR, Tillery KF, Hill DL. Disposition of 2-hydroxy-4-methoxybenzophenone in rats dosed orally, intravenously, or topically. J Toxicol Environ Health. 1986; 19(4):491–502. 10.1080/15287398609530947 3783768
12 Mutlu E, Garner CE, Wegerski CJ, McDonald JD, McIntyre BS, Doyle-Eisele M, Waidyanatha S. Metabolism and disposition of 2-hydroxy-4-methoxybenzophenone, a sunscreen ingredient, in Harlan Sprague Dawley rats and B6C3F1/N mice; a species and route comparison. Xenobiotica. 2020; 50(6):689–704. 10.1080/00498254.2019.1680906 31613170
13 Kadry AM, Okereke CS, Abdel-Rahman MS, Friedman MA, Davis RA. Pharmacokinetics of benzophenone-3 after oral exposure in male rats. J Appl Toxicol. 1995; 15(2):97–102. 10.1002/jat.2550150207 7782565
14 Jeon H-K, Sarma SN, Kim Y-J, Ryu J-C. Toxicokinetics and metabolisms of benzophenone-type UV filters in rats. Toxicology. 2008; 248(2-3):89–95. 10.1016/j.tox.2008.02.009 18448226
15 Okereke CS, Abdel-Rhaman MS, Friedman MA. Disposition of benzophenone-3 after dermal administration in male rats. Toxicol Lett. 1994; 73(2):113–122. 10.1016/0378-4274(94)90101-5 8048080
16 Nakagawa Y, Suzuki T. Metabolism of 2-hydroxy-4-methoxybenzophenone in isolated rat hepatocytes and xenoestrogenic effects of its metabolites on MCF-7 human breast cancer cells. Chem Biol Interact. 2002; 139(2):115–128. 10.1016/S0009-2797(01)00293-9 11823001
17 Kamikyouden N, Sugihara K, Watanabe Y, Uramaru N, Murahashi T, Kuroyanagi M, Sanoh S, Ohta S, Kitamura S. 2, 5-Dihydroxy-4-methoxybenzophenone: A novel major in vitro metabolite of benzophenone-3 formed by rat and human liver microsomes. Xenobiotica. 2013; 43(6):514–519. 10.3109/00498254.2012.742217 23190297
18 Nakamura N, Inselman AL, White GA, Chang CW, Trbojevich RA, Sephr E, Voris KL, Patton RE, Bryant MS, Harrouk W. Effects of maternal and lactational exposure to 2‐hydroxy‐4‐methoxybenzone on development and reproductive organs in male and female rat offspring. Birth Defects Res B Dev Reprod Toxicol. 2015; 104(1):35–51. 10.1002/bdrb.21137 25707689
19 Janjua NR, Kongshoj B, Andersson AM, Wulf HC. Sunscreens in human plasma and urine after repeated whole‐body topical application. J Eur Acad Dermatol Venereol. 2008; 22(4):456–461. 10.1111/j.1468-3083.2007.02492.x 18221342
20 Jiang R, Roberts M, Collins D, Benson H. Absorption of sunscreens across human skin: An evaluation of commercial products for children and adults. Br J Clin Pharmacol. 1999;48:635–637. 10.1046/j.1365-2125.1999.00056.x 10583038
21 Gustavsson Gonzalez H, Farbrot A, Larkö O. Percutaneous absorption of benzophenone‐3, a common component of topical sunscreens. Clin Exp Dermatol. 2002; 27(8):691–694. 10.1046/j.1365-2230.2002.01095.x 12472548
22 Tarazona I, Chisvert A, Salvador A. Determination of benzophenone-3 and its main metabolites in human serum by dispersive liquid–liquid microextraction followed by liquid chromatography tandem mass spectrometry. Talanta. 2013;116:388–395. 10.1016/j.talanta.2013.05.075 24148420
23 Gonzalez H, Farbrot A, Larkö O, Wennberg AM. Percutaneous absorption of the sunscreen benzophenone‐3 after repeated whole‐body applications, with and without ultraviolet irradiation. Br J Dermatol. 2006; 154(2):337–340. 10.1111/j.1365-2133.2005.07007.x 16433806
24 Zamoiski RD, Cahoon EK, Freedman DM, Linet MS. Self-reported sunscreen use and urinary benzophenone-3 concentrations in the United States: NHANES 2003–2006 and 2009–2012. Environ Res. 2015;142:563–567. 10.1016/j.envres.2015.08.006 26298557
25 Huo W, Cai P, Chen M, Li H, Tang J, Xu C, Zhu D, Tang W, Xia Y. The relationship between prenatal exposure to BP-3 and Hirschsprung’s disease. Chemosphere. 2016;144:1091–1097. 10.1016/j.chemosphere.2015.09.019 26454118
26 Rodríguez-Gómez R, Zafra-Gómez A, Camino-Sánchez F, Ballesteros O, Navalón A. Gas chromatography and ultra high performance liquid chromatography tandem mass spectrometry methods for the determination of selected endocrine disrupting chemicals in human breast milk after stir-bar sorptive extraction. J Chromatogr A. 2014;1349:69–79. 10.1016/j.chroma.2014.04.100 24861790
27 Hines EP, Mendola P, von Ehrenstein OS, Ye X, Calafat AM, Fenton SE. Concentrations of environmental phenols and parabens in milk, urine and serum of lactating North Carolina women. Reprod Toxicol. 2015;54:120–128. 10.1016/j.reprotox.2014.11.006 25463527
28 Matta MK, Zusterzeel R, Pilli NR, Patel V, Volpe DA, Florian J, Oh L, Bashaw E, Zineh I, Sanabria C, et al. Effect of sunscreen application under maximal use conditions on plasma concentration of sunscreen active ingredients: A randomized clinical trial. JAMA. 2019; 321(21):2082–2091. 10.1001/jama.2019.5586 31058986
29 Miller D, Wheals BB, Beresford N, Sumpter JP. Estrogenic activity of phenolic additives determined by an in vitro yeast bioassay. Environ Health Perspect. 2001; 109(2):133–138. 10.1289/ehp.109-1240632 11266322
30 Suzuki T, Kitamura S, Khota R, Sugihara K, Fujimoto N, Ohta S. Estrogenic and antiandrogenic activities of 17 benzophenone derivatives used as UV stabilizers and sunscreens. Toxicol Appl Pharmacol. 2005; 203(1):9–17. 10.1016/j.taap.2004.07.005 15694459
31 Schreurs RH, Sonneveld E, Jansen JH, Seinen W, van der Burg B. Interaction of polycyclic musks and UV filters with the estrogen receptor (ER), androgen receptor (AR), and progesterone receptor (PR) in reporter gene bioassays. Toxicol Sci. 2004; 83(2):264–272. 10.1093/toxsci/kfi035 15537743
32 Kunz PY, Fent K. Multiple hormonal activities of UV filters and comparison of in vivo and in vitro estrogenic activity of ethyl-4-aminobenzoate in fish. Aquat Toxicol. 2006; 79(4):305–324. 10.1016/j.aquatox.2006.06.016 16911836
33 Schreurs R, Lanser P, Seinen W, van der Burg B. Estrogenic activity of UV filters determined by an in vitro reporter gene assay and an in vivo transgenic zebrafish assay. Arch Toxicol. 2002; 76(5-6):257–261. 10.1007/s00204-002-0348-4 12107642
34 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of 2-hydroxy-4-methoxybenzophenone (CAS No. 131-57-7) administered in feed to Sprague Dawley (Hsd:Sprague Dawley SD) rats and B6C3F1/N mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2020. NTP Technical Report No. 597. https://ntp.niehs.nih.gov/go/tr597
35 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines: OPPTS 890.1250: Estrogen receptor binding assay using rat uterine cytosol (ER-RUC). Washington, DC: U.S. Environmental Protection Agency, Office of Pollution Prevention and Toxics; 2009., EPA/740/C-09/005.
36 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines: OPPTS 890.1300: Estrogen receptor transcriptional activation (human cell line (HeLa9903)) Washington, DC: U.S. Environmental Protection Agency, Office of Pollution Prevention and Toxics; 2009. EPA/740/C-09/006
37 Schlumpf M, Cotton B, Conscience M, Haller V, Steinmann B, Lichtensteiger W. In vitro and in vivo estrogenicity of UV screens. Environ Health Perspect. 2001; 109(3):239–244. 10.1289/ehp.01109239 11333184
38 Coronado M, De Haro H, Deng X, Rempel MA, Lavado R, Schlenk D. Estrogenic activity and reproductive effects of the UV-filter oxybenzone (2-hydroxy-4-methoxyphenyl-methanone) in fish. Aquat Toxicol. 2008; 90(3):182–187. 10.1016/j.aquatox.2008.08.018 18930325
39 Kim S, Jung D, Kho Y, Choi K. Effects of benzophenone-3 exposure on endocrine disruption and reproduction of Japanese medaka (Oryzias latipes)—A two generation exposure study. Aquat Toxicol. 2014;155:244–252. 10.1016/j.aquatox.2014.07.004 25064457
40 National Toxicology Program (NTP). Technical report on the toxicity studies of 2-hydroxy-4-methoxybenzophenone (CAS No. 131-57-7) adminstered topically and in dosed feed to F344/N rats and B6C3F1 mice. Research Triangle Park, NC: US Department of Health and Human Services. Public Health Service, National Institutes of Health; 1992. NTP Toxicity Report No. 021. https://ntp.niehs.nih.gov/ntp/htdocs/st_rpts/tox021.pdf
41 National Toxicology Program (NTP). Final report on the reproductive toxicity of 2-hydroxy-4-methoxybenzophenone in CD-1 Swiss mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1990. RACB88076. https://ntp.niehs.nih.gov/testing/types/repro/abstracts/racb88076/index-63.html
42 Daston GP, Gettings SD, Carlton BD, Chudkowski M, Davis RA, Kraus AL, Luke CF, Oellette RE, Re TA, Hoberman AM. Assessment of the reproductive toxic potential of dermally applied 2-hydroxy-4-methoxybenzophenone to male B6C3F1 mice. Toxicol Sci. 1993; 20(1):120–124. 10.1093/toxsci/20.1.120 8432422
43 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines: OPPTS 890.1600: Uterotrophic assay. Washington, DC: U.S. Environmental Protection Agency, Office of Pollution Prevention and Toxics; 2009.
44 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines: OPPTS 890.1150: Androgen receptor binding (rat prostate cytosol). Washington, DC: U.S. Environmental Protection Agency, Office of Pollution Prevention and Toxics; 2009.
45 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines: OPPTS 890.1400: Hershberger bioassay. Washington, DC: U.S. Environmental Protection Agency, Office of Pollution Prevention and Toxics; 2009.
46 U.S. Environmental Protection Agency (USEPA). Endocrine disruptor screening program test guidelines: OPPTS 890.1200: Aromatase (human recombinant). Washington, DC: U.S. Environmental Protection Agency, Office of Pollution Prevention and Toxics; 2009.
47 Wolff MS, Engel SM, Berkowitz GS, Ye X, Silva MJ, Zhu C, Wetmur J, Calafat AM. Prenatal phenol and phthalate exposures and birth outcomes. Environ Health Perspect. 2008; 116(8):1092–1097. 10.1289/ehp.11007 18709157
48 Philippat C, Mortamais M, Chevrier C, Petit C, Calafat AM, Ye X, Silva MJ, Brambilla C, Pin I, Charles M-A. Exposure to phthalates and phenols during pregnancy and offspring size at birth. Environ Health Perspect. 2011; 120(3):464–470. 10.1289/ehp.1103634 21900077
49 DiNardo JC, Downs CA. Can oxybenzone cause Hirschsprung’s disease? Reprod Toxicol. 2019; 86:98–100. 10.1016/j.reprotox.2019.02.014 30831214
50 Lewerenz H-J, Lewerenz G, Plass R. Akute und subchronische toxizitätsuntersuchungen des UV-absorbers MOB an ratten. Food Cosmet Toxicol. 1972; 10(1):41–50. 10.1016/S0015-6264(72)80045-2
51 European Chemical Agency (ECHA). Entry for: Oxybenzone (CAS No. 131-57-5). Helsinki, Finland: European Union; 2017. https://echa.europa.eu/registration-dossier/-/registered-dossier/5515/7/5/1
52 Trevisi P, Vincenzi C, Chieregato C, Guerra L, Tosti A. Sunscreen sensitization: A three-year study. Dermatology. 1994; 189(1):55–57. 10.1159/000246784 8003788
53 Agin PP, Ruble K, Hermansky SJ, McCarthy TJ. Rates of allergic sensitization and irritation to oxybenzone‐containing sunscreen products: A quantitative meta‐analysis of 64 exaggerated use studies. Photodermatol Photoimmunol Photomed. 2008; 24(4):211–217. 10.1111/j.1600-0781.2008.00363.x 18717962
54 Bernard FX, Barrault C, Deguercy A, De Wever B, Rosdy M. Development of a highly sensitive in vitro phototoxicity assay using the SkinEthic reconstructed human epidermis. Cell Biol Toxicol. 2000; 16(6):391–400. 10.1023/A:1007604612003 11254165
55 Food and Drug Administration (FDA). Sunscreen drug products for over-the-counter human use; Proposal to amend and lift stay on monograph preliminary regulatory impact analysis. White Oak, MD: FDA Office of Policy, Plannin and Legislation; 2019. FDA-1978-N-0018. https://www.fda.gov/media/122882/download
56 Food and Drug Administration (FDA). Nonprescription sunscreen drug products – Safety and effectiveness data: Guidance for industry. Silver Sping, MD: FDA Center for Drug Evaluation and Research; 2016. https://www.fda.gov/media/94513/download
57 National Toxicology Program (NTP). Testing status of 2-hydroxy-4-methoxybenzophenone 10260-S. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020. https://ntp.niehs.nih.gov/whatwestudy/testpgm/status/ts-10260-s.html
58 Blystone CR, Kissling GE, Bishop JB, Chapin RE, Wolfe GW, Foster PM. Determination of the di-(2-ethylhexyl) phthalate NOAEL for reproductive development in the rat: Importance of the retention of extra animals to adulthood. Toxicol Sci. 2010; 116(2):640–646. 10.1093/toxsci/kfq147 20484383
59 U.S. Environmental Protection Agency (USEPA). Guidelines for developmental toxicity risk assessment. Washington, DC: U.S. Environmental Protection Agency, Risk Assessment Forum; 1991. EPA Document No. EPA/600/FR-91/001.
60 Makris SL, Solomon HM, Clark R, Shiota K, Barbellion S, Buschmann J, Ema M, Fujiwara M, Grote K, Hazelden KP. Terminology of developmental abnormalities in common laboratory mammals (version 2). Congenit Anom (Kyoto). 2009; 49(3):123–246. 10.1111/j.1741-4520.2009.00239.x 20002907
61 Cora MC, Kooistra L, Travlos G. Vaginal cytology of the laboratory rat and mouse: Review and criteria for the staging of the estrous cycle using stained vaginal smears. Toxicol Pathol. 2015; 43(6):776–793. 10.1177/0192623315570339 25739587
62 Staples RE. Detection of visceral alterations in mammalian fetuses. Teratology. 1974; 9(3):A37–A38. 4832056
63 Stuckhardt JL, Poppe SM. Fresh visceral examination of rat and rabbit fetuses used in teratogenicity testing. Teratog Carcinog Mutagen. 1984; 4(2):181–188. 10.1002/tcm.1770040203 6145223
64 Thompson R. Foundations of Physiological Psychology. New York, NY: Harper and Row Publishers; 1967. Chapter 4, Basic neuroanatomy; p. 79–82.
65 Marr MC, Price CJ, Myers CB, Morrissey RE. Developmental stages of the CD (Sprague-Dawley) rat skeleton after maternal exposure to ethylene glycol. Teratology. 1992; 46(2):169–181. 10.1002/tera.1420460210 1440420
66 Tyl RW, Marr M. Developmental and Reproductive Toxicology. 2nd ed. New York, NY: Taylor and Francis Group; 2006. Developmental toxicity texting – methodology; p. 201–261.
67 Robb GW, Amann R, Killian G. Daily sperm production and epididymal sperm reserves of pubertal and adult rats. J Reprod Fertil. 1978; 54(1):103–107. 10.1530/jrf.0.0540103 712697
68 Mutlu E, Pierfelice J, McIntyre BS, Cunny HC, Kissling GE, Burback B, Waidyanatha S. Simultaneous quantitation of 2-hydroxy-4-methoxybenzophenone, a sunscreen ingredient, and its metabolites in Harlan Sprague Dawley rat plasma following perinatal dietary exposure. J Anal Toxicol. 2017; 41(9):744–754. 10.1093/jat/bkx070 28977387
69 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
70 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
71 Kupper LL, Portier CJ, Hogan M, Yamamoto E. The impact of litter effects on dose-response modeling in teratology. Biometrics. 1986; 42(1):85–98. 10.2307/2531245 3719065
72 Rao JN, Scott A. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
73 Fung KY, Krewski D, Rao JN, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
74 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
75 Piegorsch W, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London, England: CRC Press; 1997.
76 Portier CJ, Bailer A. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Toxicol Sci. 1989; 12(4):731–737. 10.1093/toxsci/12.4.731 2744275
77 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
78 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
79 Dixon WJ, Massey FJ. Introduction to Statistical Analysis. New York: McGraw-Hill; 1957. 10.2307/2332898
80 Tukey J. Easy summaries – numerical and graphical. Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 43–44.
81 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
82 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
83 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
84 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168.
85 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
86 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
87 Dunn OJ. Multiple comparison using RANK sums. Technometrics. 1964;6:241–252. 10.1080/00401706.1964.10490181
88 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
89 Davison AC, Hinkley DV. Bootstrap Methods and Their Application. Cambridge, UK: Cambridge University Press; 1997. 10.1017/CBO9780511802843
90 Datta S, Satten GA. Rank-sum tests for clustered data. J Am Stat Assoc. 2005; 100(471):908–915. 10.1198/016214504000001583
91 Hommel G. A stagewise rejective multiple test procedure based on a modified Bonferroni test. Biometrika. 1988; 75(2):383–386. 10.1093/biomet/75.2.383
92 Hothorn LA. Statistical evaluation of toxicological bioassays – a review. Toxicol Res (Camb). 2014; 3(6):418–432. 10.1039/C4TX00047A
93 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
94 Kalbfleisch JD, Lawless JF. The analysis of panel data under a Markov assumption. J Am Stat Assoc. 1985; 80(392):863–871. 10.1080/01621459.1985.10478195
95 Code of Federal Regulations (CFR). Title 21 Part 58.
96 National Toxicology Program (NTP). DART-05: Growth and clinical finding tables (I), pathology tables (PA), developmental and reproductive tables (R) from NTP modified one generation dose range finding study and modified one generation main study studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020.
97 National Toxicology Program (NTP). NTP technical report on the multigenerational reproductive toxicology study of ethinyl estradiol (CAS No. 57-63-6) in Sprague-Dawley rats (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2010. NTP Technical Report No. 547. https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr547.pdf?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr547
98 National Toxicology Program (NTP). Multigenerational reproductive assessment of 4-methylimidazole administered in the diet to Hsd:Sprague Dawley SD rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020.
99 National Toxicology Program (NTP). Reproductive and developmental toxicity assessment of butyl paraben in Hsd: Sprague Dawley SD rats following feed exposure. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020.
100 National Toxicology Program (NTP). Nonneoplastic lesion atlas: Kidney - nephropathy, obstructive. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2014. https://ntp.niehs.nih.gov/nnl/urinary/kidney/neobs/index.htm
101 Hard GC, Flake GP, Sills RC. Re-evaluation of kidney histopathology from 13-week toxicity and two-year carcinogenicity studies of melamine in the F344 rat: Morphologic evidence of retrograde nephropathy. Vet Pathol. 2009; 46(6):1248–1257. 10.1354/vp.08-VP-0317-F-FL 19605901
102 Krause M, Klit A, Blomberg Jensen M, Soeborg T, Frederiksen H, Schlumpf M, Lichtensteiger W, Skakkebaek NE, Drzewiecki KT. Sunscreens: Are they beneficial for health? An overview of endocrine disrupting properties of UV-filters. Int J Androl. 2012; 35(3):424–436. 10.1111/j.1365-2605.2012.01280.x 22612478
103 Molina-Molina JM, Escande A, Pillon A, Gomez E, Pakdel F, Cavailles V, Olea N, Ait-Aissa S, Balaguer P. Profiling of benzophenone derivatives using fish and human estrogen receptor-specific in vitro bioassays. Toxicol Appl Pharmacol. 2008; 232(3):384–395. 10.1016/j.taap.2008.07.017 18706922
104 Juárez-Rojas L, Vigueras-Villasenor RM, Casillas F, Retana-Marquez S. Gradual decrease in spermatogenesis caused by chronic stress. Acta Histochem. 2017; 119(3):284–291. 10.1016/j.acthis.2017.02.004 28236448
105 Nirupama M, Devaki M, Nirupama R, Yajurvedi HN. Chronic intermittent stress-induced alterations in the spermatogenesis and antioxidant status of the testis are irreversible in albino rat. J Physiol Biochem. 2013; 69(1):59–68. 10.1007/s13105-012-0187-6 22820994
106 Santamaria CG, Abud JE, Porporato MM, Meyer N, Zenclussen AC, Kass L, Rodriguez HA. The UV filter benzophenone 3, alters early follicular assembly in rat whole ovary cultures. Toxicol Lett. 2019;303:48–54. 10.1016/j.toxlet.2018.12.016 30599193
107 Zhang H, Taya K, Nagaoka K, Yoshida M, Watanabe G. Neonatal exposure to 17alpha-ethynyl estradiol (EE) disrupts follicle development and reproductive hormone profiles in female rats. Toxicol Lett. 2017;276:92–99. 10.1016/j.toxlet.2017.05.014 28522409
108 National Center for Toxicological Research (NCTR). NCTR Technical Report: Effect of oxybenzone on fertility and early embryonic development in Sprague-Dawley rats (segment I). Jefferson, AR: National Center for Toxicological Research; 2016. Report E02186.01. https://ntp.niehs.nih.gov/nctr/e0218601_report_508.pdf
109 Ramaley JA. Effects of corticosterone treatment on puberty in female rats. Proceedings of the Society for Experimental Biology and Medicine Society for Experimental Biology and Medicine (New York, NY). 1976; 153(3):514-517. 10.3181/00379727-153-39581 10.3181/00379727-153-39581
110 Engelbregt MJ, Houdijk ME, Popp-Snijders C, Delemarre-van de Waal HA. The effects of intra-uterine growth retardation and postnatal undernutrition on onset of puberty in male and female rats. Pediatr Res. 2000; 48(6):803–807. 10.1203/00006450-200012000-00017 11102550
111 Bronson FH. Puberty in female rats: Relative effect of exercise and food restriction. Am J Physiol. 1987; 252(1 Pt 2):R140–R144. 10.1152/ajpregu.1987.252.1.R140 3812725
112 National Toxicology Program (NTP). NTP developmental and reproductive toxicity technical report on the modified one-generation study of 2-ethylhexyl p-methoxycinnamate (CASRN 5466-77-3) administered in feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats with prenatal, reproductive performance, and subchronic assessments in F1 offspring (DRAFT). Research Triangle Park, NC: US Department of Health and Human Services, Public Health Service, National Toxicology Program; 2020., DART 06.
113 National Toxicology Program (NTP). NTP developmental and reproductive toxicity technical report on the modified one-generation study of bisphenol AF (CASRN 1478-61-1) administered in feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats with prenatal, reproductive performance, and subchronic assessments in F1 offspring (DRAFT). Research Triangle Park, NC: US Department of Health and Human Services, Public Health Service, National Toxicology Program; 2020., DART 08.
114 Ostby JS, Gray LE, Kavlock RJ, Ferrell JM. The postnatal effects of prenatal exposure to low doses of nitrofen (2,4-dichlorophenyl-p-nitrophenyl ether) in Sprague-Dawley rats. Toxicology. 1985; 34(4):285–297. 10.1016/0300-483X(85)90139-8 3992587
115 Gray LE Jr, Kavlock RJ, Chernoff N, Ostby J, Ferrell J. Postnatal developmental alterations following prenatal exposure to the herbicide 2,4-dichlorophenyl-p-nitrophenyl ether: A dose response evaluation in the mouse. Toxicol Appl Pharmacol. 1983; 67(1):1–14. 10.1016/0041-008X(83)90239-9 6845349
116 McIntyre BS, Barlow NJ, Foster PM. Androgen-mediated development in male rat offspring exposed to flutamide in utero: Permanence and correlation of early postnatal changes in anogenital distance and nipple retention with malformations in androgen-dependent tissues. Toxicol Sci. 2001; 62(2):236–249. 10.1093/toxsci/62.2.236 11452136
117 Bowman CJ, Barlow NJ, Turner KJ, Wallace DG, Foster PM. Effects of in utero exposure to finasteride on androgen-dependent reproductive development in the male rat. Toxicol Sci. 2003; 74(2):393–406. 10.1093/toxsci/kfg128 12773767
118 Stanić D, Plecas-Solarovic B, Mirkovic D, Jovanovic P, Dronjak S, Markovic B, Dordevic T, Ignjatovic S, Pesic V. Oxytocin in corticosterone-induced chronic stress model: Focus on adrenal gland function. Psychoneuroendocrinology. 2017;80:137–146. 10.1016/j.psyneuen.2017.03.011 28343139
119 Woo DC, Hoar RM. “Apparent hydronephrosis” as a normal aspect of renal development in late gestation of rats: The effect of methyl salicylate. Teratology. 1972; 6(2):191–196. 10.1002/tera.1420060210 5079708
120 Solecki R, Bergmann B, Burgin H, Buschmann J, Clark R, Druga A, Van Duijnhoven EA, Duverger M, Edwards J, Freudenberger H, et al. Harmonization of rat fetal external and visceral terminology and classification. Report of the Fourth Workshop on the Terminology in Developmental Toxicology, Berlin, 18-20 April 2002. Reprod Toxicol. 2003; 17(5):625–637. 10.1016/S0890-6238(03)00092-3 14555201
121 LabDiet. Advanced Protocol^®^ Verified Casein Diet 10 IF. 2017. https://www.labdiet.com/cs/groups/lolweb/@labdiet/documents/web_content/mdrf/mdi4/~edisp/ducm04_028427.pdf