# Conclusions

Under the conditions of this modified one-generation (MOG) study, there was equivocal evidence of reproductive toxicity of 2-hydroxy-4-methoxybenzophenone (2H4MBP) in Hsd:Sprague Dawley^®^ SD^®^ rats based on a decrease in F_2_ litter size in both the prenatal and reproductive performance cohorts.

Under the conditions of this MOG study, there was some evidence of developmental toxicity of 2H4MBP in Hsd:Sprague Dawley^®^ SD^®^ rats based on the observed postnatal growth retardation. The relationship of the increased occurrence of diaphragmatic and hepatodiaphragmatic hernias in F_1_ adults and F_2_ pups to 2H4MBP exposure is unclear.

Exposure to 2H4MBP was not associated with signals consistent with alterations in estrogenic, androgenic, or antiandrogenic action. Exposure to 2H4MBP was associated with lower F_1_ and F_2_ mean body weights; this effect on body weight contributed to the apparent 2H4MBP-related decreases in male reproductive organ weights. Mating and littering were not significantly affected by 2H4MBP exposure. Exposure to 2H4MBP was associated with nonneoplastic kidney lesions in the F_0_, F_1_, and F_2_ generations. Expected estrogenic responses were observed in the EE group.