# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-DART-05.^96^

## Dose Range-finding Study

### Maternal Findings

#### Viability and Clinical Observations

One F_0_ rat in the 3,000 ppm group was euthanized on study day 5 before the start of dosed feed administration due to the presence of excessive red eye discharge (too early to determine pregnancy status); this finding was not attributed to 2H4MBP exposure (Appendix E (https://tools.niehs.nih.gov/cebs3/views/?action=main.dataReview&bin_id=14485)). No clinical observations were attributed to 2-hydroxy-4-methoxybenzophenone (2H4MBP) exposure in any group during gestation or lactation (Appendix E (https://tools.niehs.nih.gov/cebs3/views/?action=main.dataReview&bin_id=14485)).

#### Body Weights and Feed Consumption

F_0_ females exposed to 50,000 ppm 2H4MBP displayed lower body weights than the control group (Table 4; Figure 5). The mean body weight of dams in the 50,000 ppm group on gestation day (GD) 21 was significantly decreased by 11% compared to the control group, and the mean body weight gain of dams in the 50,000 ppm group over gestation (GD 6–21) was significantly decreased by 35%. This difference was attributed to a transient body weight loss over the GD 6–9 interval and lower body weight gains over most of the subsequent intervals and not attributed to smaller litters or lower fetal weights (Appendix E). F_0_ females exposed to 10,000 or 25,000 ppm 2H4MBP displayed similar 20% significant decreases in body weight gain over the GD 6–21 interval, which were attributed to lower body weights during the early gestation period (Table 4).

Table 4 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation and Lactation (Dose Range-finding Study)

Parameter^a,b^ | 0 ppm | 3,000 ppm | 10,000 ppm | 25,000 ppm | 50,000 ppm
Gestation Body Weight
Gestation Day
6 | 224.0 ± 4.3 (10) | 223.2 ± 4.6 (11) | 225.2 ± 2.8 (6) | 226.9 ± 3.6 (5) | 224.8 ± 5.0 (12)
9 | 236.6 ± 4.4* (10) | 238.0 ± 4.6 (11) | 233.7 ± 3.5 (6) | 233.8 ± 3.0 (5) | 224.0 ± 4.1 (12)
12 | 248.6 ± 5.4** (10) | 245.9 ± 5.3 (11) | 243.7 ± 3.7 (6) | 241.6 ± 3.5 (5) | 226.9 ± 5.5** (12)
15 | 264.9 ± 6.4* (10) | 261.8 ± 5.1 (11) | 258.1 ± 5.1 (6) | 258.7 ± 3.8 (5) | 247.9 ± 5.0 (12)
18 | 298.8 ± 7.5** (10) | 295.0 ± 5.3 (11) | 290.2 ± 7.1 (6) | 288.7 ± 5.3 (5) | 268.6 ± 5.9** (12)
21 | 343.3 ± 11.3** (7) | 327.7 ± 7.3 (8) | 321.7 ± 8.3 (6) | 323.8 ± 6.2 (5) | 305.4 ± 7.1** (9)
Gestation Weight Change
Gestation Day Interval
6–21 | 120.7 ± 6.1** (7) | 106.1 ± 7.4 (8) | 96.5 ± 5.9** (6) | 96.9 ± 4.5** (5) | 78.0 ± 2.5** (9)
6–9 | 12.7 ± 1.2** (10) | 14.8 ± 0.7 (11) | 8.5 ± 1.7* (6) | 6.9 ± 1.4** (5) | −0.8 ± 1.3** (12)
9–12 | 11.9 ± 1.5** (10) | 7.9 ± 1.4 (11) | 9.9 ± 2.8 (6) | 7.9 ±1.4 (5) | 2.9 ± 2.3** (12)
12–15 | 16.3 ± 1.3* (10) | 15.9 ± 1.4 (11) | 14.5 ± 2.0 (6) | 17.0 ± 1.9 (5) | 21.1 ± 1.6 (12)
15–18 | 33.9 ± 2.9** (10) | 33.3 ± 2.8 (11) | 32.1 ± 3.8 (6) | 30.0 ± 2.7 (5) | 20.7 ± 1.3** (12)
18–21 | 40.6 ± 2.5* (7) | 35.1 ± 2.9 (8) | 31.6 ± 2.1* (6) | 35.1 ± 2.2 (5) | 33.4 ± 1.2 (9)
Lactation Body Weight
Lactation Day
1 | 247.5 ± 7.7** (7) | 241.8 ± 7.1 (7) | 239.0 ± 5.0 (6) | 232.2 ± 8.6 (5) | 221.7 ± 5.0** (9)
4 | 261.7 ± 6.2** (7) | 256.1 ± 6.5 (7) | 251.4 ± 5.6 (6) | 245.5 ± 6.7 (5) | 225.1 ± 5.7** (9)
7 | 266.7 ± 9.9* (5) | 262.8 ± 9.2 (5) | 263.4 ± 5.0 (6) | 246.2 ± 8.2 (5) | 234.6 ± 5.6* (6)
14 | 277.8 ± 11.8** (5) | 269.0 ± 10.6 (5) | 280.3 ± 5.0 (6) | 252.7 ± 7.5 (5) | 222.8 ± 10.5** (6)
21 | 265.7 ± 8.1* (5) | 269.4 ± 8.3 (5) | 267.5 ± 3.5 (6) | 252.3 ± 6.6 (5) | 222.5 ± 15.2* (6)
Lactation Weight Change
Lactation Day Interval
1–21 | 18.7 ± 3.4 (5) | 32.1 ± 9.4 (5) | 28.5 ± 3.6 (6) | 20.2 ± 3.6 (5) | 3.8 ± 11.6 (6)
1–4 | 14.3 ± 3.1* (7) | 14.2 ± 4.8 (7) | 12.3 ± 2.3 (6) | 13.3 ± 3.3 (5) | 3.3 ± 2.7 (9)
4–7 | 5.1 ± 2.0 (5) | 6.2 ± 4.3 (5) | 12.0 ± 0.7 (6) | 0.7 ± 6.1 (5) | 13.7 ± 2.3 (6)
7–14 | 11.1 ± 3.5 (5) | 6.2 ± 8.5 (5) | 16.9 ± 2.3 (6) | 6.5 ± 6.9 (5) | −11.8 ± 8.5 (6)
14–21 | −12.1 ± 4.3 (5) | 0.4 ± 8.0 (5) | −12.8 ± 3.3 (6) | −0.4 ± 2.9 (5) | −0.3 ± 9.5 (6)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (n); body weight data are presented in grams. Changes in n are the result of animal removal (i.e., biological sampling, animal health concerns).

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

Figure 5

Growth Curves for F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation and Lactation (Dose Range-finding Study)

Growth curves shown for F_0_ female rats during (A) gestation and (B) lactation. Information for statistical significance in maternal weights is provided in Table 4.

Lactation mean body weights were significantly decreased (16%) in dams exposed to 50,000 ppm 2H4MBP relative to the control group (Table 4; Figure 5). This decrease was similar in magnitude to that observed at the end of gestation and likely related to the significantly decreased body weights observed during gestation.

In general, feed consumption during gestation in the 2H4MBP-exposed groups was higher than in the control group (Table 5). Feed consumption was significantly increased at several time intervals in the 25,000 and 50,000 ppm groups and likely signifies poor palatability and subsequent powdered feed wastage (when the animals were trying to find more palatable feed in the jar). This was also supported by the observation of apparent feed in the animals’ bedding. 2H4MBP intake for F_0_ females in the 3,000, 10,000, 25,000, and 50,000 ppm 2H4MBP groups, based on measured feed consumption and dietary concentrations for GD 6–21 interval, was approximately 215, 695, 2,086, and 6,426 mg 2H4MBP/kg body weight/day (mg/kg/day), respectively (Table 5).

Table 5 Summary of Feed and Test Article Consumption of F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation and Lactation (Dose Range-finding Study)

Parameter^a,b,c^ | 0 ppm | 3,000 ppm | 10,000 ppm | 25,000 ppm | 50,000 ppm
Feed Consumption (g/animal/day)^d^
Gestation Day Interval
6–21 | 18.1 ± 0.7** (7) | 18.7 ± 0.4 (7) | 18.0 ± 0.8 (5) | 21.8 ± 1.5* (4) | 32.0 ± 1.5** (9)
6–9 | 16.3 ± 0.6** (10) | 16.5 ± 0.4 (11) | 14.6 ± 0.7 (5) | 28.4 ± 4.7 (5) | 39.3 ± 2.7** (12)
9–12 | 16.6 ± 0.8 (10) | 17.4 ± 0.3 (11) | 18.3 ± 1.5 (6) | 18.3 ± 1.2 (5) | 19.3 ± 2.0 (9)
12–15 | 16.8 ± 0.9** (10) | 18.5 ± 0.4 (11) | 17.9 ± 0.9 (6) | 20.6 ± 1.1** (4) | 42.4 ± 3.0** (11)
15–18 | 19.9 ± 0.7* (10) | 21.2 ± 0.6 (11) | 19.7 ± 1.0 (6) | 21.2 ± 1.1 (5) | 17.8 ± 0.9 (11)
18–21 | 20.1 ± 0.9** (7) | 21.3 ± 0.8 (7) | 18.8 ± 1.0 (6) | 24.1 ± 2.3 (5) | 34.7 ± 2.7** (9)
Lactation Day Interval
1–14 | 47.5 ± 1.2 (5) | 49.3 ± 2.1 (5) | 47.9 ± 4.0 (6) | 43.6 ± 3.4 (5) | 53.6 ± 2.5 (6)
1–4 | 33.2 ± 1.4** (7) | 34.2 ± 2.4 (7) | 37.9 ± 7.2 (6) | 43.3 ± 4.7 (5) | 52.8 ± 3.7** (9)
4–7 | 42.1 ± 1.4 (5) | 41.6 ± 2.6 (5) | 44.6 ± 5.8 (6) | 32.5 ± 3.0 (5) | 35.1 ± 5.3 (4)
7–14 | 55.8 ± 1.5 (5) | 58.1 ± 2.1 (5) | 53.5 ± 2.8 (6) | 48.5 ± 5.5 (5) | 56.3 ± 3.6 (4)
Chemical Intake (mg/kg/day)^e,f^
GD 6–21 | 0.0 ± 0.0 (7) | 214.5 ± 4.7 (7) | 695.2 ± 30.4 (5) | 2,085.7 ± 161.2 (4) | 6,426.4 ± 355.5 (9)
LD 1–14 | 0.0 ± 0.0 (5) | 576.7 ± 18.4 (5) | 1,858.3 ± 173.8 (6) | 4,460.1 ± 310.8 (5) | 12,028.5 ± 715.5 (6)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ± standard error (n), where n = the number of dams. Feed consumption is not reported for nonpregnant animals during the gestation or lactation phase.

^b^ Changes in n are the result of animal removal (i.e., biological sampling, animal health concerns). Additional animals removed as outliers include: GD 6–9 (one value in the 10,000 ppm group), GD 12–15 (one value in the 25,000 ppm group), GD 18–21 (one value in the 3,000 ppm group), and GD 6–21 (one value each in the 3,000, 10,000, and 25,000 ppm groups).

^c^ For each dam, calculation of consumption values for the GD 6–21 and LD 1–14 intervals was performed using all valid data for the animal, even if data were unavailable for some of the subintervals.

^d^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^f^ No statistical analysis performed on the chemical intake data.

2H4MBP exposure was not associated with lower feed consumption during lactation (Table 5). 2H4MBP intake for F_0_ females in the 3,000, 10,000, 25,000, and 50,000 ppm 2H4MBP groups, based on feed consumption and dietary concentrations for lactation days (LDs) 1–14, was approximately 577, 1,858, 4,460, and 12,029 mg/kg/day, respectively (Table 5).

#### Maternal Reproductive Performance

Across all exposure groups, 13 out of 57 time-mated F_0_ females were not pregnant: four in the control group; two each in the 3,000, 10,000, and 50,000 ppm groups; and three in the 25,000 ppm group (Table 6). There were no toxicologically relevant effects of 2H4MBP exposure on the proportion of dams that produced viable litters or on gestation length. There was no effect of 2H4MBP exposure on initial mean litter size or sex ratio.

Table 6 Summary of the Reproductive Performance of F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation (Dose Range-finding Study)

Parameter^a^ | 0 ppm | 3,000 ppm | 10,000 ppm | 25,000 ppm | 50,000 ppm
Time-mated Females (GD 6) | 14^b^ | 13^b,c^ | 8 | 8 | 14^b^
Females Pregnant (%) | 10 (71.4) | 11 (78.6) | 6 (75.0) | 5 (62.5) | 12 (85.7)
Females Not Pregnant (%) | 4 (28.6) | 2 (15.4) | 2 (25.0) | 3 (37.5) | 2 (14.3)
Dams Not Delivering with Evidence of Pregnancy (%) | 0 (0.0)^d^ | 1 (12.5)^d^ | 0 (0.0) | 0 (0.0) | 0 (0.0)^d^
Dams with Litters on PND 0 (%)^e^ | 7 (100.0)^d^ | 7 (87.5)^d^ | 6 (100.0) | 5 (100.0) | 9 (100.0)^d^
Gestation Length (days)^f,g,h^ | 22.1 ± 0.1 (7) | 22.3± 0.2* (7) | 22.0 ± 0.0* (6) | 22.2 ± 0.2 (5) | 22.1 ± 0.1 (9)
Live Litter Size on PND 0^f,h^ | 11.4 ± 0.7 (7) | 10.9 ± 0.9 (7) | 10.7 ± 1.4 (6) | 11.8 ± 0.7 (5) | 11.8 ± 0.7 (9)
PND 1 Pup Weight^h,i,j^ | 7.11 ± 0.09** 80 (7) | 6.82 ± 0.19 74 (7) | 6.39 ± 0.10* 64 (6) | 6.58 ± 0.31 59 (5) | 6.31 ± 0.14** 106 (9)
Percent Live Male Pups/Litter^f,h^ | 53.02 ± 5.86 (7) | 47.64 ± 4.93 (7) | 41.05 ± 4.66 (6) | 47.84 ± 4.76 (5) | 53.46 ± 3.80 (9)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; PND = postnatal day.

^a^ Animals removed from the study between mating and littering were excluded from calculations of % littered females.

^b^ Includes six time-mated (pregnant) rats used for biological sample collection for methods development.

^c^ Excludes animal euthanized moribund on study day 5.

^d^ Excludes three pregnant rats used for biological sample collection on GD 18.

^e^ Percentage is the number of littered females/pregnant females. Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^f^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^g^ Gestation length calculated for time-mated females that delivered a litter.

^h^ Data are displayed as mean ± standard error (n).

^i^ n = the number of pups examined (number of litters).

^j^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

### F_1_ Offspring Findings

#### Pup Viability and Body Weights

2H4MBP exposure was associated with a reduction in the mean number of live pups per litter in the 25,000 and 50,000 ppm groups (approximately 2–3 pups/litter from PND 0 through PND 28) (Table 7; Appendix E). Over the lactation period, there were 20 dead pups (from five litters) in the 25,000 ppm group and 16 dead pups (from five litters) in the 50,000 ppm group, compared to 3 dead pups (from two litters) in the control group. In the 25,000 ppm group, 12 of the 20 dead pups were from a single litter. In the 50,000 ppm group, 10 of the 16 dead pups were from a single litter (Appendix E). Male and female pup mean body weights of these exposed groups were significantly decreased (25%–50%) compared to those of control pups (Table 8; Figure 6, Figure 7). Adverse F_1_ pup clinical observations in the 25,000 and 50,000 ppm groups were consistent with the effects of 2H4MBP exposure on pup survival (Appendix E). Findings included observations of pups found dead, cannibalized, missing, no milk band, bruised, stained fur, cold to touch, or emaciated. There were no notable gross findings in the limited number of F_1_ offspring that received a necropsy. Necropsy findings for pups found dead on or after PND 1 were limited to the absence of milk/food in the stomach (Appendix E). Pups in the 10,000 ppm group displayed mean body weights that were lower (4%–16%) than those of the control group.

Table 7 Summary of F_1_ Litter Size and Pup Survival Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone (Dose Range-finding Study)

Postnatal Day | 0 ppm | 3,000 ppm | 10,000 ppm | 25,000 ppm | 50,000 ppm
No. of Live Pups (Litters)^a^
0 | 80 (7) | 76 (7) | 64 (6) | 59 (5) | 106 (9)
Total Litter Size^b^ ^,c^
0 | 11.7 ± 0.6 (7) | 11.7 ± 1.1 (7) | 11.0 ± 1.5 (6) | 12.2 ± 0.5 (5) | 12.0 ± 0.6 (9)
Live Litter Size ^b,c^
0 | 11.4 ± 0.7 (7) | 10.9 ± 0.9 (7) | 10.7 ± 1.4 (6) | 11.8 ± 0.7 (5) | 11.8 ± 0.7 (9)
1 | 11.4 ± 0.7 (7) | 10.6 ± 0.9 (7) | 10.7 ± 1.4 (6) | 11.8 ± 0.7 (5) | 11.8 ± 0.7 (9)
4 | 11.4 ± 0.7 (7) | 10.6 ± 0.9 (7) | 10.7 ± 1.4 (6) | 10.6 ± 1.3 (5) | 10.8 ± 0.7 (9)
7 | 11.2 ± 0.8 (5) | 10.6 ± 1.2 (5) | 10.7 ± 1.4 (6) | 9.6 ± 2.0 (5) | 9.7 ± 1.1 (6)
14 | 11.0 ± 0.8 (5) | 10.0 ± 1.0 (5) | 10.7 ± 1.4 (6) | 10.3 ± 0.6 (4) | 9.5 ± 1.1 (6)
21 | 11.0 ± 0.8 (5) | 10.0 ± 1.0 (5) | 10.7 ± 1.4 (6) | 10.3 ± 0.6 (4) | 9.5 ± 1.1 (6)
28 | 11.0 ± 0.8 (5) | 10.0 ± 1.0 (5) | 10.7 ± 1.4 (6) | 10.3 ± 0.6 (4) | 9.2 ± 1.0 (6)
No. of Dead Pups (Litters)^a^
0 | 2 (1) | 6 (3) | 2 (2) | 2 (1) | 2 (2)
1–4 | 0 (0) | 2 (2) | 0 (0) | 6 (1) | 9 (2)
5–28 | 1 (1) | 4 (3) | 0 (0) | 12 (4) | 5 (4)
1–28 | 1 (1) | 6 (4) | 0 (0) | 18 (4) | 14 (4)
Dead per Litter^b,c^
0 | 0.29 ± 0.29 (7) | 0.86 ± 0.46 (7) | 0.33 ± 0.21 (6) | 0.40 ± 0.40 (5) | 0.22 ± 0.15 (9)
1–4 | 0.00 ± 0.00 (7) | 0.29 ± 0.18 (7) | 0.00 ± 0.00 (6) | 1.20 ± 1.20 (5) | 1.00 ± 0.88 (9)
5–28 | 0.20 ± 0.20 (5) | 0.80 ± 0.37 (5) | 0.00 ± 0.00 (6) | 2.40 ± 0.98 (5) | 0.83 ± 0.31 (6)
1–28 | 0.20 ± 0.20 (5) | 1.20 ± 0.49 (5) | 0.00 ± 0.00 (6) | 3.60 ± 2.14 (5) | 2.33 ± 1.56 (6)
Survival Ratio^b,c^
0 | 0.97 ± 0.03 (7) | 0.94 ± 0.03 (7) | 0.97 ± 0.02 (6) | 0.97 ± 0.03 (5) | 0.98 ± 0.01 (9)
1–4 | 1.00 ± 0.00 (7) | 0.97 ± 0.02 (7) | 1.00 ± 0.00 (6) | 0.90 ± 0.10 (5) | 0.93 ± 0.06 (9)
5–28 | 0.98 ± 0.02 (5) | 0.94 ± 0.03 (5) | 1.00 ± 0.00 (6) | 0.70 ± 0.18 (5) | 0.90 ± 0.04 (6)
1–28 | 0.98 ± 0.02 (5) | 0.90 ± 0.04 (5) | 1.00 ± 0.00 (6) | 0.70 ± 0.18 (5) | 0.83 ± 0.10 (6)

^a^ n = the number of pups (number of litters).

^b^ Data are displayed as mean ± standard error of the litter means (n), where n = number of litters.

^c^ F_1_ litter size and survival endpoints were analyzed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests. All calculations are based on the last litter observation of the day.

Table 8 Summary of F_1_ Male and Female Pup Mean Body Weights Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone (Dose Range-finding Study)^a,b^

Postnatal Day^c^ | 0 ppm | 3,000 ppm | 10,000 ppm | 25,000 ppm | 50,000 ppm
Male
1 | 7.32 ± 0.11** 42 (7)^d^ | 7.02 ± 0.21 36 (7) | 6.55 ± 0.13* 26 (6) | 6.70 ± 0.30 28 (5) | 6.43 ± 0.17** 57 (9)
4 | 11.19 ± 0.22** 42 (7) | 10.67 ± 0.42 36 (7) | 9.40 ± 0.21** 26 (6) | 8.39 ± 0.60** 24 (5) | 8.52 ± 0.27** 52 (9)
7 | 15.60 ± 0.38** 29 (5) | 14.87 ± 0.99 25 (5) | 13.49 ± 0.37 26 (6) | 11.50 ± 0.90** 22 (5) | 11.46 ± 0.30** 29 (6)
14 | 30.11 ± 1.01** 28 (5) | 30.79 ± 1.19 25 (5) | 26.41 ± 0.61 26 (6) | 25.51 ± 1.78* 17 (4) | 21.76 ± 1.09** 29 (6)
21 | 46.44 ± 1.26** 28 (5) | 47.97 ± 1.47 25 (5) | 40.77 ± 1.24 26 (6) | 36.77 ± 2.24** 17 (4) | 27.90 ± 2.52** 29 (6)
28 | 81.97 ± 1.60** 28 (5) | 82.02 ± 3.18 25 (5) | 70.77 ± 1.73 26 (6) | 63.24 ± 4.94** 17 (4) | 40.22 ± 4.02** 29 (6)
Female
1 | 6.83 ± 0.03** 38 (7) | 6.67 ± 0.18 38 (7) | 6.30 ± 0.09 38 (6) | 6.44 ± 0.35 31 (5) | 6.10 ± 0.11** 49 (9)
4 | 10.40 ± 0.15** 38 (7) | 10.02 ± 0.39 38 (7) | 9.11 ± 0.12* 38 (6) | 8.38 ± 0.78** 29 (5) | 8.25 ± 0.24** 45 (9)
7 | 14.66 ± 0.33** 27 (5) | 14.73 ± 0.74 28 (5) | 13.00 ± 0.21 38 (6) | 12.02 ± 0.99* 26 (4) | 11.27 ± 0.29** 29 (6)
14 | 27.07 ± 1.22** 27 (5) | 29.49 ± 0.91 25 (5) | 26.16 ± 0.23 38 (6) | 24.64 ± 2.14 24 (4) | 22.41 ± 1.54* 28 (6)
21 | 42.83 ± 1.07** 27 (5) | 44.69 ± 1.99 25 (5) | 39.35 ± 0.38 38 (6) | 36.71 ± 2.71 24 (4) | 28.02 ± 3.07** 28 (6)
28 | 74.01 ± 1.15** 27 (5) | 74.13 ± 2.42 25 (5) | 66.77 ± 1.00 38 (6) | 58.12 ± 5.84* 24 (4) | 37.12 ± 4.90** 26 (6)
Male and Female
1 | 7.11 ± 0.09** 80 (7) | 6.82 ± 0.19 74 (7) | 6.39 ± 0.10* 64 (6) | 6.58 ± 0.31 59 (5) | 6.31 ± 0.14** 106 (9)
4 | 10.84 ± 0.18** 80 (7) | 10.33 ± 0.38 74 (7) | 9.19 ± 0.14** 64 (6) | 8.41 ± 0.69** 53 (5) | 8.43 ± 0.23** 97 (9)
7 | 15.16 ± 0.35** 56 (5) | 14.69 ± 0.84 53 (5) | 13.13 ± 0.23* 64 (6) | 11.48 ± 0.92** 48 (5) | 11.37 ± 0.29** 58 (6)
14 | 29.08 ± 0.90** 55 (5) | 30.11 ± 0.99 50 (5) | 26.15 ± 0.27 64 (6) | 24.98 ± 1.94 41 (4) | 22.09 ± 1.26** 57 (6)
21 | 44.85 ± 1.24** 55 (5) | 46.32 ± 1.42 50 (5) | 39.82 ± 0.66 64 (6) | 36.67 ± 2.57* 41 (4) | 28.03 ± 2.76** 57 (6)
28 | 78.55 ± 1.66** 55 (5) | 77.73 ± 2.39 50 (5) | 68.27 ± 1.14 64 (6) | 60.37 ± 5.39** 41 (4) | 38.80 ± 4.43** 55 (6)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^b^ Data are displayed as mean ± standard error of the litter means. Body weight data are presented in grams.

^c^ As litters were not standardized, pup weights throughout the entire postnatal period were adjusted using the total live litter size on postnatal day 1.

^d^ n = the number of pups examined (number of litters).

Figure 6

Lactation Growth Curves for F_1_ Male Pups Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone (Dose Range-finding Study)

Information for statistical significance in male pup weights is provided in Table 8.

Figure 7

Lactation Growth Curves for F_1_ Female Pups Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone (Dose Range-finding Study)

Information for statistical significance in female pup weights is provided in Table 8.

### Exposure Concentration Selection Rationale for the Modified One-Generation Study of 2-Hydroxy-4-methoxybenzophenone

The selection of 30,000 ppm 2H4MBP as the high exposure concentration was based on the maternal toxicity observed at 50,000 ppm and the marginal effect on pup survival at 25,000 ppm (most of the pup deaths at this exposure concentration were attributed to a single dam). Exposure concentration spacing (3,000, 10,000, 30,000 ppm) was selected to achieve a no-observed-adverse-effect level and to avoid excessive overlap of the ingested doses due to increased feed consumption during pregnancy. The selection of the 0.05 ppm ethinyl estradiol (EE) exposure concentration as a reference positive control was informed by the National Center for Toxicological Research studies,^97^ which demonstrated that this exposure concentration accelerated time to vaginal opening (VO), delayed time to balanopreputial separation (BPS), caused transient alterations in estrous cyclicity, and induced male mammary gland hyperplasia.

## Modified One-Generation Study

### F_0_ Generation: Maternal Findings

Maternal effects were evaluated from GD 6 through LD 28, as shown in Figure 8. Viability, clinical observations, gestation and lactation mean body weights, feed consumption, and reproductive performance results are presented below.

Figure 8

Design of the Modified One-Generation Study – F_0_ Generation

GD = gestation day; LD = lactation day; PND = postnatal day.

#### F_0_ Viability and Clinical Observations

2H4MBP exposure did not affect viability of the F_0_ females (Appendix E). One female in the EE group was removed on GD 11 and was subsequently diagnosed with lymphoma. Given the singular incidence and early onset, this occurrence was not considered related to EE exposure. No clinical observations were attributed to 2H4MBP exposure (Appendix E).

#### F_0_ Gestation Body Weights and Feed Consumption

F_0_ females exposed to 10,000 or 30,000 ppm 2H4MBP displayed lower gestation mean body weights and body weight gains (Table 9; Figure 9). On GD 21, female mean body weights were significantly decreased by 5% and 10% compared to those of control animals in the 10,000 and 30,000 ppm 2H4MBP groups, respectively. Body weight gains between GD 6 and GD 21 were significantly decreased by 11%, 25%, and 35% compared to those of the control group in the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups, respectively (Table 9). There was a transient loss in mean body weight (−1.0 g) between GD 6 and GD 9 in the 30,000 ppm 2H4MBP group compared to a gain of 13.7 g in the control group. This interval corresponds to the first interval the females were administered dosed feed and likely reflects lower palatability (feed wastage) of the dosed feed; this is also consistent with what was observed in the dose range-finding study. Females in the 30,000 ppm groups also exhibited significantly decreased (approximately 12%–20%) body weight gains in the GD 15–18 and GD 18–21 intervals (Table 9). Gestational mean body weights and weight gains in the EE group were less than those in the control group. Body weight gain in the EE group over the GD 6–21 interval was significantly decreased by approximately 35% compared to the control group (Table 9). There was no effect of 2H4MBP exposure on F_0_ female mean body weights during gestation in the 3,000 ppm group. There was no reduction in litter size on PND 0 or pup mean body weight on PND 1 in the 2H4MBP-exposed groups (Appendix E), suggesting the lower relative maternal body weights were due to a maternal body weight effect of 2H4MBP rather than an effect on the collective weight of the uterine contents. Pup body weight on PND 1, but not litter size, was significantly decreased (12%) in the 0.05 ppm EE group (Appendix E) and likely contributed to the lower maternal body weight gain of that group compared to the control group.

Table 9 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation

Parameter^a,b^ | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^c^
Gestation Body Weight
Gestation Day
6 | 242.9 ± 2.7 (22) | 239.4 ± 3.2 (21) | 239.0 ± 2.7 (22) | 239.1 ± 2.7 (20) | 241.4 ± 3.9 (20)
9 | 256.6 ± 2.9** (22) | 251.4 ± 3.5 (21) | 249.5 ± 2.9 (22) | 238.1 ± 2.5** (20) | 242.3 ± 3.6** (20)
12 | 272.4 ± 3.1** (22) | 266.3 ± 3.5 (21) | 262.1 ± 3.1* (22) | 251.7 ± 2.7** (20) | 251.5 ± 3.6** (19)
15 | 292.2 ± 3.0** (22) | 285.1 ± 3.8 (21) | 280.5 ± 3.2* (22) | 268.8 ± 2.9** (20) | 264.5 ± 3.6** (19)
18 | 331.4 ± 3.7** (22) | 325.2 ± 4.5 (21) | 317.6 ± 3.9* (22) | 303.3 ± 3.4** (20) | 297.4 ± 5.1** (19)
21 | 375.2 ± 4.5** (22) | 366.6 ± 5.6 (21) | 357.2 ± 4.7** (21) | 338.5 ± 3.9** (20) | 328.2 ± 5.1** (19)
Gestation Weight Change
Gestation Day Interval
6–21 | 132.3 ± 3.0** (22) | 127.1 ± 3.4 (21) | 118.1 ± 3.2** (22) | 99.3 ± 2.5** (20) | 86.4 ± 3.8** (19)
3–6 | 14.6 ± 1.4 (22) | 12.7 ± 1.2 (21) | 14.3 ± 1.1 (22) | 12.5 ± 1.0 (20) | 15.0 ± 1.6 (20)
6–9 | 13.7 ± 0.6** (22) | 12.0 ± 0.9 (21) | 10.5 ± 1.0* (22) | -1.0 ± 1.4** (20) | 0.9 ± 1.1** (20)
9–12 | 15.8 ± 0.9* (22) | 15.0 ± 0.9 (21) | 12.7 ± 0.7* (22) | 13.5 ± 0.9 (20) | 9.3 ± 0.8** (19)
12–15 | 19.8 ± 0.8* (22) | 18.8 ± 0.8 (21) | 18.4 ± 0.8 (22) | 17.2 ± 1.1 (20) | 13.0 ± 0.9** (19)
15–18 | 39.2 ± 1.4** (22) | 40.2 ± 1.5 (21) | 37.0 ± 1.4 (22) | 34.5 ± 1.3* (20) | 32.9 ± 2.6* (19)
18–21 | 43.8 ± 1.7** (22) | 41.3 ± 1.9 (21) | 40.7 ± 1.4 (21) | 35.1 ± 1.2** (20) | 30.8 ± 1.7** (19)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol.

^a^ Data are displayed as mean ± standard error (n); body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

Figure 9

Growth Curves for F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation

EE = ethinyl estradiol. Information for statistical significance in maternal weights is provided in Table 9.

Despite sporadic differences, neither 2H4MBP nor EE exposure adversely affected feed consumption during gestation (Table 10). Observed higher feed consumption in the 30,000 ppm group likely represented feed wastage. 2H4MBP intake for F_0_ females in the 3,000, 10,000, and 30,000 ppm groups, based on feed consumption and dietary concentrations over the GD 6–21 interval, was approximately 205, 697, and 2,644 mg/kg/day, respectively (Table 10). EE intake during gestation was approximately 0.004 mg/kg/day.

Table 10 Summary of Feed and Test Article Consumption of F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation

Gestation Day Interval^a,b^ | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^c^
Feed Consumption (g/animal/day)^d^
6–21 | 20.0 ± 0.3* (22) | 19.6 ± 0.4 (21) | 19.7 ± 0.5 (22) | 23.9 ± 1.0* (20) | 20.3 ± 1.5 (19)
3–6 | 17.5 ± 0.3 (22) | 16.7 ± 0.4 (21) | 16.8 ± 0.4 (22) | 17.0 ± 0.5 (20) | 17.4 ± 0.5 (20)
6–9 | 17.8 ± 0.3** (22) | 17.6 ± 0.4 (21) | 20.4 ± 1.5 (22) | 30.8 ± 2.7** (20) | 20.7 ± 2.5 (20)
9–12 | 18.7 ± 0.3* (22) | 18.6 ± 0.4 (20)^e^ | 18.2 ± 0.6 (22) | 17.1 ± 0.6 (20) | 13.9 ± 0.5** (19)^f^
12–15 | 19.2 ± 0.4 (22) | 19.4 ± 0.4 (21) | 18.9 ± 0.6 (22) | 27.2 ± 2.3* (20) | 26.9 ± 3.3 (19)
15–18 | 22.6 ± 0.4** (22) | 21.7 ± 0.4 (21) | 21.0 ± 0.4** (22) | 21.3 ± 0.3** (20) | 18.9 ± 0.6** (16)^g^
18–21 | 21.8 ± 0.6 (22) | 20.6 ± 0.5 (21) | 20.0 ± 0.6 (22) | 23.3 ± 1.8 (20) | 19.7 ± 1.2** (19)
Chemical Intake (mg/kg/day)^h,i^
GD 6–21 | 0.0 ± 0.0 (22) | 204.5 ± 2.7 (21) | 697.3 ± 15.4 (22) | 2,644.4 ± 109.2 (20) | 3.8 ± 0.2 (19)^j^

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol; GD = gestation day.

^a^ Data are displayed as mean ± standard error (n), where n = the number of dams. Feed consumption is not reported for nonpregnant animals during the gestation phase.

^b^ For each dam, calculation of consumption values for the GD 6–21 interval was performed using all valid data for the animal, even if data were unavailable for some of the subintervals.

^c^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^d^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Change in n is due to the exclusion of improbable data.

^f^ Excludes one dam euthanized moribund on GD 11.

^g^ Excludes feed consumption from cages where excess feed spillage was observed.

^h^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^i^ No statistical analysis performed on the chemical intake data.

^j^ EE intake presented as µg/kg/day.

#### Maternal Reproductive Performance

Across all exposure groups, 20 of 125 time-mated rats were not pregnant: three each in the control and 10,000 ppm groups, four in the 3,000 ppm group, five in the 30,000 ppm group, and five in the EE group (Table 11; Appendix E). There was no effect of 2H4MBP exposure on the proportion of dams that produced viable litters or on gestation length. There was no effect of 2H4MBP exposure on initial mean litter size, PND 1 pup weight, or sex ratio. PND 1 pup weight in the EE group was significantly decreased by 12% compared to the control group (Table 11). Anogenital distance (AGD) measurements are presented in Appendix E.

Table 11 Summary of the Reproductive Performance of F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Gestation

Parameter^a^ | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^b^
Time-mated Females (GD 6) | 25 | 25 | 25 | 25 | 25
Females Pregnant (%) | 22 (88.0) | 21 (84.0) | 22 (88.0) | 20 (80.0) | 20 (80.0)
Females Not Pregnant (%) | 3 (12.0) | 4 (16.0) | 3 (12.0) | 5 (20.0) | 5 (20.0)
Dams with Litters on PND 0 (%)^c^ | 22 (100.0) | 21 (100.0) | 22 (100.0) | 20 (100.0) | 18 (90.0)^d^
Gestation Length (days)^e,f,g^ | 22.3 ± 0.1 (22) | 22.3 ± 0.1 (21) | 22.2 ± 0.1 (22) | 22.4 ± 0.1 (20) | 22.4 ± 0.1 (18)
Live Litter Size on PND 0^e,g^ | 12.8 ± 0.6 (22) | 13.0 ± 0.6 (21) | 13.3 ± 0.6 (22) | 12.4 ± 0.4 (20) | 13.2 ± 0.6 (18)
PND 1 Pup Weight^g,h,i^ | 7.07 ± 0.10* 271 (22) | 7.04 ± 0.09 260 (20)^j^ | 6.78 ± 0.10 276 (22) | 6.78 ± 0.09 234 (20) | 6.21 ± 0.18** 208 (18)
Percent Live Male Pups/Litter^e,g^ | 46.62 ± 2.90 (22) | 52.08 ± 3.48 (21) | 48.11 ± 4.01 (22) | 52.56 ± 2.93 (20) | 47.76 ± 3.60 (18)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol; GD = gestation day; PND = postnatal day.

^a^ Animals removed from the study between mating and littering were excluded from calculations of % littered females.

^b^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^c^ Percentage is the number of littered females/pregnant females. Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^d^ Excludes one dam euthanized moribund on GD 11.

^e^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ Gestation length was calculated for time-mated females that delivered a litter.

^g^ Data are displayed as mean ± standard error (n).

^h^ n = the number of pups examined (number of litters).

^i^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^j^ Excludes one litter in which the lone pup died on PND 1.

#### Lactation Body Weights and Feed Consumption

F_0_ females in the 10,000 and 30,000 ppm 2H4MBP and 0.5 ppm EE groups displayed lower mean body weights during lactation compared to the control group (Figure 10; Table 12). The magnitude of response (approximately 5%–15% decrease) in female body weights at LD 1 and LD 28 was similar to that observed at the end of the gestation interval. These observations collectively suggest that the lower lactation body weight was a consequence of exposure to 2H4MBP or EE during gestation and not a direct effect of exposure during lactation.

Figure 10

Growth Curves for F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Lactation

EE = ethinyl estradiol. Information for statistical significance in maternal weights is provided in Table 12.

Table 12 Summary of Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of F_0_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Lactation^a^

Lactation Day | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^b^
Body Weight (g)^c^
1 | 268.3 ± 3.7** (22) | 260.5 ± 3.8 (21) | 254.6 ± 3.7** (22) | 244.6 ± 3.3** (20) | 227.5 ± 3.5** (18)
28 | 286.3 ± 3.1** (22) | 282.1 ± 3.7 (20) | 277.1 ± 3.0 (22) | 257.4 ± 4.0** (20) | 249.3 ± 4.0** (15)^d^
Body Weight Gain (g)^c^
1–28 | 18.0 ± 3.3 (22) | 22.0 ± 2.4 (20) | 22.6 ± 2.8 (22) | 12.7 ± 3.2 (20) | 23.8 ± 1.9 (15)
Feed Consumption^e^
1–13 (g/animal/day) | 45.3 ± 0.9* (22) | 45.8 ± 1.0 (19) | 43.8 ± 0.9 (22) | 43.6 ± 1.9 (18) | 41.3 ± 1.7* (15)
1–13 (g/kg/day) | 157.9 ± 3.3 (22) | 161.4 ± 3.0 (19) | 159.1 ± 3.0 (22) | 170.7 ± 7.2 (18) | 168.9 ± 7.4 (15)
Chemical Intake (mg/kg/day)^f,g^
1–13 | 0.0 ± 0.0 (22) | 484.1 ± 8.9 (19) | 1,590.7 ± 29.6 (22) | 5,119.8 ± 216.3 (18) | 8.4 ± 0.4 (15)^h^

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol.

^a^ Data are displayed as mean ± standard error (n), where n = the number of dams.

^b^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^c^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ Excludes body weights of two dams on lactation day (LD) 4 and one dam on LD 7 scheduled for removal.

^e^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis performed on the chemical intake data.

^h^ EE intake presented as µg/kg/day.

Feed consumption during lactation was similar among the groups. Dam 2H4MBP intake based on feed consumption and dietary concentrations during lactation from LD 1 through LD 13 (until the pups started consuming feed) for the 3,000, 10,000, and 30,000 ppm groups was approximately 484, 1,591, and 5,120 mg/kg/day, respectively (Table 12). EE intake during lactation was approximately 0.008 mg/kg/day.

Collectively, these data indicate that 30,000 ppm 2H4MBP and 0.05 ppm EE challenged the dams (as demonstrated by significantly decreased GD 6–21 body weights), without adversely affecting F_1_ litter size.

### F_1_ Generation: Preweaning

F_1_ male and female rats were evaluated during the preweaning period from PND 0 through PND 28, as shown in Figure 11. Viability, clinical observations, and mean body weight results are presented below.

Figure 11

Design of the Modified One-Generation Study – F_1_ Generation: Preweaning

GD = gestation day; LD = lactation day; PND = postnatal day.

#### F_1_ Viability and Clinical Observations

Clinical observations were noted in individual pups in all groups, including the control groups, and were typically indicative of a pup not thriving (e.g., cold to the touch, no milk in the stomach) (Appendix E). There was no effect of 2H4MBP on pup survival (Table 13). The mean number of live pups per litter appeared to be reduced in the 0.05 ppm EE group on PND 4 relative to the control group. That reduction reflected three litters that did not survive to PND 4, resulting in a higher number of dead or missing (presumed dead) pups and a lower survival ratio for the PND 1–4 interval relative to the control group. On PND 28, there was a slight, but significant, decrease in mean litter size in the EE group relative to the control group.

Table 13 Summary of F_1_ Litter Size and Pup Survival Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone

Postnatal Day | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^a^
No. of Live Pups (Litters)^b^
0 | 273 (22) | 263 (21) | 282 (22) | 234 (20) | 221 (18)
Total Litter Size^c,d^
0 | 12.8 ± 0.6 (22) | 13.0 ± 0.6 (21) | 13.3± 0.6 (22) | 12.4 ± 0.4 (20) | 13.2 ± 0.6 (18)
Live Litter Size^c,d^
0 | 12.4 ± 0.6 (22) | 12.5 ± 0.7 (21) | 12.8 ± 0.5 (22) | 11.7 ± 0.4 (20) | 12.3 ± 0.6 (18)
1 | 12.3 ± 0.6 (22) | 13.0 ± 0.5 (20)^e^ | 12.5 ± 0.5 (22) | 11.7 ± 0.4 (20) | 11.6 ± 0.8 (18)
4 (prestandardization) | 12.2 ± 0.5 (22) | 13.0 ± 0.5 (20) | 12.5 ± 0.5 (22) | 11.7 ± 0.4 (20) | 11.4 ± 0.9 (16)
4 (poststandardization) | 7.9 ± 0.1 (22) | 7.9 ± 0.1 (20) | 7.9 ± 0.1 (22) | 8.0 ± 0.0 (20) | 7.9 ± 0.1 (15)^f^
13 | 7.9 ± 0.1 (22) | 7.9 ± 0.1 (20) | 7.8 ± 0.1 (22) | 7.9 ± 0.1 (20) | 7.9 ± 0.1 (15)
21 | 7.9 ± 0.1 (22) | 7.9 ± 0.1 (20) | 7.7 ± 0.1 (22) | 7.8 ± 0.1 (20) | 7.9 ± 0.1 (15)
28 | 7.8 ± 0.1 (22) | 7.9 ± 0.1 (20) | 7.7 ± 0.1 (22) | 7.8 ± 0.1 (20) | 7.4 ± 0.2** (15)
No. of Dead Pups (Litters)^b^
0 | 9 (4) | 9 (7) | 11 (9) | 13 (7) | 17 (5)
1–4 | 5 (4) | 4 (4) | 7 (4) | 1 (1) | 39 (5)
5–28 | 1 (1) | 1 (1) | 4 (3) | 4 (4) | 0 (0)
Dead per Litter^c,d^
0 | 0.41 ± 0.28 (22) | 0.43 ± 0.15 (21) | 0.50 ± 0.14 (22) | 0.65 ± 0.27 (20) | 0.94 ± 0.47 (18)
1–4 | 0.23 ± 0.11 (22) | 0.19 ± 0.09 (21) | 0.32 ± 0.19 (22) | 0.05 ± 0.05 (20) | 2.17 ± 1.13 (18)
5–28 | 0.05 ± 0.05 (22) | 0.05 ± 0.05 (20) | 0.18 ± 0.11 (22) | 0.20 ± 0.09 (20) | 0.00 ± 0.00 (15)
Survival Ratio^c,d^
0 | 0.97 ± 0.02 (22) | 0.94 ± 0.03 (21) | 0.96 ± 0.01 (22) | 0.95 ± 0.02 (20) | 0.93 ± 0.03 (18)
1–4 | 0.98 ± 0.01 (22) | 0.94 ± 0.05 (21) | 0.98 ± 0.01 (22) | 1.00 ± 0.00 (20) | 0.83 ± 0.09 (18)
5–28 | 0.99 ± 0.01 (22) | 0.99 ± 0.01 (20) | 0.98 ± 0.01 (22) | 0.98 ± 0.01 (20) | 1.00 ± 0.00 (15)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

** Statistically significant at p ≤ 0.01.

EE = ethinyl estradiol.

^a^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^b^ n = the number of pups examined (number of litters).

^c^ Data are displayed as mean ± standard error of the litter means (n), where n = the number of litters. For F_1_ pups, data are displayed as the mean of litter values ± standard error (n) of litter values (number of litters produced by F_0_ dams).

^d^ F_1_ litter size and survival endpoints were analyzed using the Jonckheere (trend) and Shirley or Dunn tests (pairwise comparisons). All calculations were based on the last litter observation of the day.

^e^ One whole litter loss occurred by postnatal day (PND) 1.

^f^ Three whole litter losses occurred by PND 4 (one by PND 1).

#### F_1_ Body Weights

##### Male Pups

An exposure concentration- and time-related reduction in male pup mean body weight per litter was observed during lactation in the 10,000 and 30,000 ppm 2H4MBP and the 0.05 ppm EE groups, relative to the control group (Table 14; Figure 12). From PND 1 through PND 28, mean body weight differences were significantly increased between the control group and the 30,000 ppm group and, to a lesser extent, the 10,000 ppm group. On PND 28, male pup mean body weights per litter were significantly decreased by 10%, 24%, and 11% compared to those of the control group in the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups, respectively.

Table 14 Summary of F_1_ Male and Female Pup Mean Body Weights Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone^a,b^

Postnatal Day | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^c^
Male
1 | 7.20 ± 0.10** 128 (22)^d^ | 7.11 ± 0.10 142 (20) | 6.82 ± 0.11* 136 (21) | 6.81 ± 0.10* 122 (20) | 6.25 ± 0.19** 101 (18)
4^e^ | 10.62 ± 0.16** 126 (22) | 10.35 ± 0.19 141 (20) | 9.80 ± 0.17** 136 (21) | 9.07 ± 0.23** 121 (20) | 8.60 ± 0.35** 91 (17)
7 | 16.47 ± 0.31** 85 (22) | 15.95 ± 0.35 80 (20) | 15.20 ± 0.39* 82 (21) | 14.17 ± 0.45** 83 (20) | 14.03 ± 0.35** 57 (15)
13 | 31.36 ± 0.42** 85 (22) | 30.78 ± 0.63 80 (20) | 28.86 ± 0.51** 82 (21) | 25.39 ± 0.74** 82 (20) | 26.80 ± 0.58** 57 (15)
28 | 89.88 ± 1.08** 85 (22) | 86.23 ± 1.53 80 (20) | 81.09 ± 1.21** 82 (21) | 67.90 ± 2.16** 80 (20) | 80.39 ± 1.15** 57 (15)
Female
1 | 6.82 ± 0.11* 143 (22) | 6.81 ± 0.10 118 (20) | 6.55 ± 0.11 140 (22) | 6.57 ± 0.09 112 (20) | 6.19 ± 0.12** 107 (17)
4^e^ | 9.99 ± 0.17** 142 (22) | 9.79 ± 0.21 118 (20) | 9.37 ± 0.18 139 (22) | 8.79 ± 0.21** 112 (20) | 8.32 ± 0.36** 102 (17)
7 | 15.49 ± 0.33** 88 (22) | 14.85 ± 0.42 78 (20) | 14.40 ± 0.39 90 (22) | 13.60 ± 0.39** 76 (20) | 13.52 ± 0.33** 61 (15)
13 | 29.79 ± 0.57** 88 (22) | 29.29 ± 0.84 77 (20) | 27.34 ± 0.62* 89 (22) | 25.06 ± 0.64** 76 (20) | 25.89 ± 0.46** 61 (15)
28 | 80.32 ± 1.19** 87 (22) | 78.12 ± 1.62 77 (20) | 73.01 ± 1.12** 88 (22) | 60.67 ± 1.53** 76 (20) | 74.62 ± 1.11** 54 (15)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol.

^a^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons. Pup weights were adjusted for covariate litter size: total live on postnatal day (PND) 1 for day 1 to day 4 and number of live pups poststandardization for later days.

^b^ Data are displayed as mean ± standard error of the litter means. Body weight data are presented in grams.

^c^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^d^ n = the number of pups examined (number of litters).

^e^ PND 4 weights are prestandardization.

Figure 12

Lactation Growth Curves for F_1_ Male Pups Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone

EE = ethinyl estradiol. Information for statistical significance in male pup weights is provided in Table 14.

##### Female Pups

An exposure concentration- and time-related reduction in female pup mean body weight per litter was observed during lactation in the groups exposed to 10,000 or 30,000 ppm 2H4MBP and 0.05 ppm EE, relative to the control group (Table 14; Figure 13). From PND 1 through PND 28, mean body weight differences became greater between the control group and the 30,000 ppm group and, to a lesser extent, the 10,000 ppm group. On PND 28, female pup mean body weights per litter were significantly decreased by 9%, 24%, and 7% compared to those of the control group in the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups, respectively.

Figure 13

Lactation Growth Curves for F_1_ Female Pups Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone

EE = ethinyl estradiol. Information for statistical significance in female pup weights is provided in Table 14.

#### F_0_ Necropsy

F_0_ dams were necropsied on PND 28 following pup weaning when the F_0_ dams were 21 weeks of age. Gross findings of pale, discolored kidneys (unilateral/bilateral) were recorded for three females in the 30,000 ppm 2H4MBP group (Appendix E). Histopathological examination identified findings of renal tubule lumen dilatation, tubule epithelium regeneration, interstitial inflammation, papilla necrosis, nephropathy, and transitional epithelium hyperplasia. Similar findings were also observed in the F_1_ and F_2_ generations exposed to 2H4MBP (Appendix E).

### F_1_ Generation: Postweaning through Sexual Maturity

F_1_ male and female rats were evaluated from postweaning through sexual maturity, as shown in Figure 14. Viability, clinical observations, mean body weights, feed consumption, and developmental endpoint results are presented below.

Figure 14

Design of the Modified One-Generation Study – F_1_ Generation: Postweaning

GD = gestation day; LD = lactation day; PND = postnatal day.

#### F_1_ Viability and Clinical Observations

Neither 2H4MBP nor EE exposure altered viability in the F_1_ generation postweaning. Clinical observations were noted in all groups, including the control groups, on a sporadic basis (Appendix E). No clinical observations showed an increase in incidence or severity in association with exposure to 2H4MBP or EE.

#### F_1_ Body Weights and Feed Consumption

##### Males (Postweaning)

Body weights between PND 28 and PND 91 were significantly decreased in males in the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups (Table 15; Figure 15). On PND 91, mean body weights of these groups were significantly decreased by 5%, 16%, and 18%, respectively, compared to those of the control group.

Table 15 Summary of Postweaning Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of All F_1_ Male Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

Postnatal Day^a^ | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^b^
Body Weight (g)^c,d^
28 | 87.6 ± 1.1** 69 (22) | 84.7 ± 1.5 65 (20) | 79.5 ± 1.2** 67 (22) | 65.7 ± 2.3** 65 (20) | 78.2 ± 1.2** 45 (15)
91 | 393.0 ± 5.0** 64 (22) | 387.6 ± 4.3 60 (20) | 372.5 ± 5.2* 62 (21) | 330.4 ± 6.8** 60 (20) | 322.8 ± 4.5** 45 (15)
Body Weight Gain (g)^c,d^
28–105 | 326.7 ± 4.5** 64 (22) | 325.9 ± 3.9 60 (20) | 319.2 ± 4.2 62 (21) | 292.3 ± 5.2** 60 (20) | 262.2 ± 4.3** 45 (15)
Postweaning Feed Consumption^e,f^
28–91 (g/animal/day) | 24.1 ± 0.4 (29) | 23.9 ± 0.4 (28) | 24.3 ± 0.3 (28) | 23.0 ± 0.5 (26) | 20.8 ± 0.3** (19)
28–91 (g/kg/day) | 87.9 ± 1.5** (29) | 89.0 ± 1.3 (28) | 94.8 ± 1.0** (28) | 100.1 ± 1.8** (26) | 91.5 ± 1.1* (19)
Chemical Intake (mg/kg/day)^g,h^
28–91 | 0.0 ± 0.0 (29) | 267.1 ± 3.9 (28) | 947.9 ± 10.4 (28) | 3,002.5 ± 53.9 (26) | 4.6 ± 0.1 (19)^i^

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol.

^a^ Data are displayed as mean ± standard error (n).

^b^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^c^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple comparisons.

^d^ n = the number of pups examined (number of litters).

^e^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ n = number of cages.

^g^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^h^ No statistical analysis performed on the chemical intake data.

^i^ EE intake presented as µg/kg/day.

Figure 15

Postweaning Growth Curves for All F_1_ Male Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

EE = ethinyl estradiol. Information for statistical significance in F_1_ male rat weights is provided in Table 15.

Overall, no adverse effects of 2H4MBP exposure on F_1_ male feed consumption were found (Table 15). Sporadic small but significant decreases in absolute feed consumption (g/animal/day) were observed in the 30,000 ppm group between PND 28 and PND 84 (Appendix E) but did not affect overall feed consumption during the postweaning period. Relative feed consumption (g/kg/day) was significantly increased in the 10,000 and 30,000 ppm groups relative to the control group during the postweaning period, likely due to the lower body weights of the animals in these groups. A significant decrease in absolute feed consumption was observed in the 0.05 ppm EE group (14% below the control group) during the postweaning period, suggesting a continued effect of EE exposure on growth during the postweaning phase. 2H4MBP intake for F_1_ males, based on feed consumption and dietary concentrations for PND 28 through PND 91, was approximately 267, 948, and 3,003 mg/kg/day at 3,000, 10,000, and 30,000 ppm 2H4MBP, respectively (Table 15). EE intake during the postweaning period was approximately 0.005 mg/kg/day.

##### Females (Postweaning)

PND 28 through PND 91 mean body weights were significantly decreased in females exposed to 30,000 ppm 2H4MBP or 0.05 ppm EE (Table 16; Figure 16). On PND 91, female mean body weights of the 30,000 ppm 2H4MBP and 0.05 ppm EE groups were significantly decreased by 14% and 17%, respectively, compared to those of the control group. The 10,000 ppm group displayed significantly decreased mean body weights (<10%) on PND 28 and PND 35 (Table 16; Appendix E), after which mean body weights were similar to those of the control group.

Table 16 Summary of Postweaning Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption of All F_1_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

Postnatal Day^a^ | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^b^
Body Weight (g)^c,d^
28 | 78.0 ± 1.0** 78 (22) | 75.6 ± 1.6 72 (20) | 71.5 ± 1.3** 77 (22) | 58.7 ± 1.6** 71 (20) | 72.3 ± 1.1** 48 (15)
91 | 246.6 ± 3.5** 63 (22) | 242.8 ± 3.2 60 (20) | 236.9 ± 3.2 62 (22) | 211.9 ± 2.7** 60 (20) | 204.3 ± 3.0** 45 (15)
Body Weight Gain (g)^c,d^
28–91 | 168.5 ± 3.0** 63 (22) | 167.1 ± 2.5 60 (20) | 165.4 ± 2.9 62 (22) | 152.7 ± 2.7** 60 (20) | 131.8 ± 3.1** 45 (15)
Postweaning Feed Consumption^e,f^
28–91 (g/animal/day) | 17.4 ± 0.3 (27) | 17.2 ± 0.3 (27) | 17.2 ± 0.3 (26) | 18.3 ± 0.3 (27) | 16.7 ± 0.5 (19)
28–91 (g/kg/day) | 95.5 ± 1.5** (27) | 95.5 ± 1.7 (27) | 98.3 ± 1.5 (26) | 116.4 ± 2.2** (27) | 108.2 ± 4.1** (19)
Chemical Intake (mg/kg/day)^g,h^
28–91 | 0.0 ± 0.0 (27) | 286.5 ± 5.0 (27) | 983.0 ± 15.3 (26) | 3,493.2 ± 65.5 (27) | 5.4 ± 0.2 (19)^i^

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

EE = ethinyl estradiol.

^a^ Data are displayed as mean ± standard error (n).

^b^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^c^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple comparisons.

^d^ n = the number of pups examined (number of litters).

^e^ Statistical analysis performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ n = number of cages.

^g^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^h^ No statistical analysis performed on the chemical intake data.

^i^ EE intake presented as µg/kg/day.

Figure 16

Postweaning Growth Curves for All F_1_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

EE = ethinyl estradiol. Information for statistical significance in F_1_ female rat weights is provided in Table 16.

In general, 2H4MBP-exposed females displayed similar feed consumption values over the postweaning period (Table 16; Appendix E). There were small (approximately 15%), but significant, increases in absolute feed consumption (g/animal/day) recorded over two weekly intervals in the 30,000 ppm 2H4MBP group between PND 42 and PND 91. There was no overall reduction in absolute feed consumption during the postweaning period in the 30,000 ppm 2H4MBP group. Relative feed consumption (g/kg/day) was significantly increased in the 30,000 ppm group relative to the control group during the postweaning period, likely the result of lower body weights of the 2H4MBP-exposed animals. Absolute feed consumption by the EE group was similar to the control group; however, as these animals weighed less, their relative feed consumption was significantly increased compared to that of the control animals. 2H4MBP intake for F_1_ females, based on feed consumption and dietary concentrations for PND 28 through PND 91, was approximately 287, 983, and 3,493 mg/kg/day at 3,000, 10,000, and 30,000 ppm 2H4MBP exposures, respectively. EE intake during the postweaning period was approximately 0.005 mg/kg/day.

### Developmental Endpoints

#### Anogenital Distance

F_1_ and F_2_ male and female offspring exposed to 2H4MBP or EE in feed did not display any alterations in mean PND 1 body-weight-adjusted AGD (Appendix E).

#### Areolae/Nipple Retention

F_1_ and F_2_ male offspring exposed to 2H4MBP or EE in feed did not display any signs of areolae/nipple retention (Appendix E).

#### Testicular Descent

F_1_ males in the 30,000 ppm 2H4MBP group displayed a significant 1-day acceleration in the mean day of testicular descent (18.0 ± 0.2) compared to the control group (19.1 ± 0.2) (Appendix E). There was no difference in the mean day of testicular descent in the F_2_ generation (Appendix E). The cumulative litter responses for the 30,000 ppm 2H4MBP group (F_1_ generation) showed an earlier age at acquisition, whereas the F_2_ generation did not display this response. The mean day of achieving testicular descent in control Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats in two other MOG studies conducted in the testing laboratory was PND 18.2 ± 0.2 and PND 18.0 ± 0.2. For NTP Reproductive Assessment by Continuous Breeding (RACB) studies, the mean day of testicular descent ranged from PND 15.3 ± 0.2 to PND 17.4 ± 0.5 over four studies.^98,99^

#### Vaginal Opening

Females exposed to 30,000 ppm 2H4MBP exhibited a significant delay in litter mean day of VO, relative to the control group (Table 17); however, when adjusted for body weight at weaning, this delay was somewhat mitigated, with the 30,000 ppm group displaying a 1-day delay. Figure 17 shows litter and adjusted litter cumulative response (%), or cumulative probability of attainment, plotted against PND for each exposure group. Exposure increases were associated with higher cumulative probabilities of attainment delays, particularly for the 30,000 ppm group, as seen in the exposure-related rightward shift of curves toward higher attainment days (Figure 17A). These shifts were less pronounced after adjustment for body weight at weaning (Figure 17B). The delay was associated with lower body weight, and these females also exhibited significantly decreased mean body weights during lactation and postweaning (Table 16; Figure 16). As expected, litter mean day of VO in the EE group was greatly accelerated (by approximately 11 days) compared to the control group (Table 17; Figure 17).

Table 17 Summary of Vaginal Opening of F_1_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

Parameter^a^ | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^b^
No. Examined^c^ | 63 (22) | 60 (20) | 62 (22) | 60 (20) | 55 (15)
No. Not Attaining^d^ | 0 | 0 | 0 | 0 | 0
Day of VO
Litter mean^e,f^ | 35.3 ± 0.2** | 35.4 ± 0.4 | 35.9 ± 0.3 | 38.1 ± 0.4** | 24.3 ± 0.3**
Adjusted litter mean^e,f,g^ | 35.9 ± 0.2* | 35.8 ± 0.3 | 35.9 ± 0.3 | 37.0 ± 0.3 | 24.3 ± 0.3**
Mean Body Weight at Acquisition (g)^h^ | 115.7 ± 1.9** | 114.3 ± 1.6 | 111.5 ± 1.6 | 109.0 ± 1.9* | 59.0 ± 1.5**
Mean Body Weight at Weaning (g)^h^ | 80.6 ± 1.1** | 78.1 ± 1.8 | 73.6 ± 1.3** | 60.7 ± 1.6** | 74.5 ± 1.2**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol; VO = vaginal opening.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^c^ No. Examined = the number of pups examined (number of litters).

^d^ No. Not Attaining = number of pups that survived to the end of the observation period without attaining VO.

^e^ Summary statistics and mixed model results are presented for animals that attained during the observation period.

^f^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^g^ Adjusted based on body weight at weaning.

^h^ Analysis of body weight at acquisition and body weight at weaning for both linear trend and pairwise comparisons performed using mixed effects models with litter as a random effect and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

Figure 17

Time to Vaginal Opening of F_1_ Female Offspring Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

EE = ethinyl estradiol. Cumulative response curves are shown for (A) litter response and (B) litter response adjusted for body weight at weaning.

#### Balanopreputial Separation

Male rats in the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups displayed a significant delay in the mean day of attaining BPS (Table 18). Figure 18 shows litter and adjusted litter cumulative response (%), or cumulative probability of attainment, plotted against PND for each exposure group. An exposure-dependent rightward shift is seen for the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups, indicating higher cumulative probabilities of attainment at later PNDs (Figure 18). When litter mean day of attainment was adjusted for body weight on day of weaning, these delays were no longer significantly different from control males (Table 18; Figure 18). The observed delay in BPS in 2H4MBP- or EE-exposed animals is likely the consequence of growth retardation as evidenced by lower mean body weights and body weight gains (Table 15; Figure 15). Three males in the 30,000 ppm 2H4MBP group had not achieved BPS as of PND 59, when checks for this marker stopped. These males were from the same litter (dam 202). Two were assigned to the reproductive performance cohort (animals 1901 and 1907) and the other (animal 1903) was assigned to the prenatal cohort. None of them demonstrated evidence of mating or resultant evidence of pregnancy. At scheduled necropsy, two of the males had achieved BPS and the other (animal 1903) had hypospadias.

Table 18 Summary of Balanopreputial Separation of F_1_ Male Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

Parameter^a^ | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^b^
No. Examined^c^ | 64 (22) | 59 (20) | 62 (21) | 60 (20) | 45 (15)
No. Not Attaining^d^ | 0 (0) | 0 (0) | 0 (0) | 3 (1) | 0 (0)
Day of BPS
Litter mean^e,f^ | 43.7 ± 0.3** | 44.0 ± 0.4 | 44.9 ± 0.3* | 47.1 ± 0.4** | 45.8 ± 0.3**
Adjusted litter mean^e,f,g^ | 44.7 ± 0.3 | 44.7 ± 0.3 | 44.8 ± 0.3 | 45.4 ± 0.3 | 44.8 ± 0.3
Proportional hazards model, p value^h^ | 0.112 | 0.956 | 0.956 | 0.852 | 0.138
Mean Body Weight at Acquisition (g)^i^ | 204.4 ± 2.9** | 203.3 ± 2.9 | 196.4 ± 2.2 | 192.1 ± 2.8** | 184.7 ± 2.2**
Mean Body Weight at Weaning (g)^i^ | 90.1 ± 1.1** | 87.4 ± 1.6 | 81.4 ± 1.2** | 68.6 ± 1.9** | 80.3 ± 1.2**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol; BPS = balanopreputial separation.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^c^ No. Examined = number of pups examined (number of litters).

^d^ No. Not Attaining = number of pups (number of litters) that survived to the end of the observation period without attaining BPS.

^e^ Summary statistics and mixed model results are presented for animals that attained during the observation period.

^f^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^g^ Adjusted based on body weight at weaning.

^h^ Statistical analysis performed using the proportional hazards model with exposure concentration and weaning weight as covariates, a random effect for litter for both trend and pairwise tests, and a Hommel adjustment for multiple comparisons. Time-to-event data for animals that did not achieve the event are included and treated as providing information up to the last day examined, with time counted as “greater than last day checked.”

^i^ Analysis of body weight at acquisition and body weight at weaning for both linear trend and pairwise comparisons performed using mixed effects models with litter as a random effect and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

Figure 18

Time to Balanopreputial Separation of F_1_ Male Offspring Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

EE = ethinyl estradiol. Cumulative response curves are shown for (A) litter response and (B) litter response adjusted for body weight at weaning.

## F_1_ Cohort Data

### Prenatal and Reproductive Performance Cohorts: Mating and Fertility

F_1_ male and female rats from the prenatal and reproductive performance cohorts were mated and evaluated for reproductive endpoints, as shown in Figure 19. Viability, clinical observations, vaginal cytology, fertility, andrology, mean body weights, and feed consumption results are presented below.

Figure 19

Design of the Modified One-Generation Study – Prenatal and Reproductive Performance Cohorts

GD = gestation day; LD = lactation day; PND = postnatal day.

#### Viability and Clinical Observations

There were no exposure-related deaths or clinical observations in F_1_ male and female rats following exposure to 2H4MBP or EE in feed (Appendix E).

#### Selection and Mating

A male and a female, or two males and two females (1:1), from each litter were allocated to the prenatal and reproductive performance cohorts, respectively, avoiding sibling mating (Figure 19). Vaginal lavage samples were collected for approximately 2 weeks prior to cohabitation and continued until evidence of mating or until the cohabitation period was completed. Estrous cyclicity data are presented in Appendix E.

#### Vaginal Cytology

Analysis of estrous cyclicity using the continuous-time Markov model demonstrated a slight but significant increase in estrus stage length in the 10,000 and 30,000 ppm 2H4MBP groups compared to the control group (Appendix E). Rats in these two groups spent more time in estrus compared to the control group (approximately 36% and 37% of the days, respectively, versus approximately 31% for the control group). A slight but significant decrease in the length of proestrus was observed in the 10,000 ppm group compared to the control group. These minimal estimated changes in stage length did not impact reproductive performance and likely represent normal biological variability and are not considered biologically adverse. There were no EE exposure-related changes in estrous stage lengths.

#### Fertility

The precoital interval and number of females that mated (i.e., those that were sperm-positive, littered, or had implantation sites) were similar among the control, 2H4MBP, and EE groups in both cohorts, indicating that neither 2H4MBP nor EE exposure negatively affected mating behavior (Table 19). The number of pregnant females was also similar among the groups, indicating that F_1_ male and female fertility were not affected by 2H4MBP or EE exposure at the concentrations examined. Respective responses observed were consistent between the cohorts.

Table 19 Summary of Mating and Fertility Performance of F_1_ Male and Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

Parameter^a^ | 0 ppm | | 3,000 ppm | | 10,000 ppm | | 30,000 ppm | | EE 0.05 ppm^b^
Parameter^a^ | RPC | PC | RPC | PC | RPC | PC | RPC | PC | RPC | PC
No. Mating Pairs | 41 | 22 | 40 | 20 | 40 | 22 | 40 | 20 | 30 | 15
No. Mated | 40 | 19 | 37 | 19 | 35 | 21 | 35 | 19 | 29 | 15
No. Females Pregnant | 35 | 18 | 37 | 18 | 33 | 20 | 33 | 19 | 28 | 15
Percent of Mated Females/Paired^c^ | 97.6 | 86.4 | 92.5 | 95.0 | 87.5 | 95.5 | 87.5 | 95.0 | 96.7 | 100.0
Precoital Interval^d,e^ | 4.7 ± 0.6 (22) | 4.3 ± 0.7 (19) | 4.8 ± 0.5 (20) | 5.3 ± 1.0 (18) | 5.1 ± 0.7 (19) | 4.1 ± 0.8 (19) | 4.2 ± 0.8 (20) | 3.9 ± 0.6 (18) | 4.0 ± 0.6 (15) | 3.4 ± 0.5 (15)

EE = ethinyl estradiol; RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^c^ Statistical analysis of the RPC performed using the Rao-Scott Cochran-Armitage test for both trend and pairwise comparisons to adjust for litter effects. Statistical analysis of the PC performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^d^ Statistical analysis of the RPC performed using a bootstrapped Jonckheere test for trend, and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons. Statistical analysis for the PC cohort performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^e^ Precoital interval in days is calculated for sperm-positive females; data are displayed as mean ± standard error (n).

#### F_1_ Reproductive Performance Cohort Andrology

There were no 2H4MBP- or EE-related effects on motile sperm, progressively motile sperm, or testis spermatid head concentration (Appendix E). Males in the 30,000 ppm 2H4MBP group displayed lower cauda epididymal sperm counts (approximately 14%) and epididymis weight (approximately 6%) relative to control animals. Testis weight was lower in the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups (approximately 6%, 6%, and 9%, respectively), relative to control animals. These findings were not associated with histopathological changes (Appendix E) or significant changes in reproductive performance (Appendix E).

#### Gestation Body Weights

As previously mentioned, F_1_ female rats exposed to 10,000 or 30,000 ppm 2H4MBP or 0.05 ppm EE displayed significantly decreased preweaning and postweaning mean body weights compared to the control group. Consequently, F_1_ female mean body weights of the 30,000 ppm 2H4MBP and 0.05 ppm EE groups in both the prenatal and reproductive performance cohorts at the time of cohabitation were lower relative to control females. Gestation body weight curves of the exposed groups in both cohorts generally paralleled the control group (Figure 20, Figure 21). Dams in both cohorts exposed to 10,000 or 30,000 ppm 2H4MBP or 0.05 ppm EE, however, displayed significantly decreased GD 0–21 mean body weight gains (approximately 13%–14%, 25%–28%, and 22%–24%, respectively) relative to the respective control group (Table 20). This difference in mean body weight gain during pregnancy might be the result of a slight reduction in litter size of one to two fewer fetuses/pups observed in these groups (Appendix E). Respective responses observed were consistent between the two cohorts.

Figure 20

Gestation Growth Curves for F_1_ Female Rats in the Reproductive Performance Cohort Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

EE = ethinyl estradiol. Information for statistical significance in F_1_ female rat weights is provided in Table 20.

Figure 21

Gestation Growth Curves for F_1_ Female Rats in the Prenatal Cohort Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

EE = ethinyl estradiol. Information for statistical significance in F_1_ female rat weights is provided in Table 20.

Table 20 Summary of Gestation Mean Body Weight Gains for F_1_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed^a,b,c^

GD Interval | 0 ppm | | 3,000 ppm | | 10,000 ppm | | 30,000 ppm | | EE 0.05 ppm^d^
GD Interval | RPC | PC | RPC | PC | RPC | PC | RPC | PC | RPC | PC
0 | 252.3 ± 5.3** (22) | 256.4 ± 4.2** (18) | 255.0 ± 3.4 (20) | 248.3 ± 6.1 (17) | 248.2 ± 3.8 (19) | 238.1 ± 3.7** (18) | 219.9 ± 3.5** (20) | 220.5 ± 3.4** (18) | 209.3 ± 4.3** (15) | 207.2 ± 2.7** (15)
6–21 | 141.6 ± 3.7** (22) | 138.9 ± 4.2** (18) | 136.2 ± 3.3 (20) | 136.4 ± 3.0 (16) | 123.3 ± 3.7** (19) | 117.9 ± 6.3* (18) | 101.1 ± 4.8** (20) | 103.6 ± 7.4** (18) | 112.9 ± 3.3** (15) | 108.4 ± 4.4** (15)
0–21 | 173.0 ± 4.3** (22) | 168.2 ± 4.5** (18) | 166.8 ± 4.1 (20) | 165.5 ± 3.9 (16) | 149.8 ± 3.6** (19) | 145.0 ± 6.6** (18) | 124.6 ± 5.9** (20) | 126.3 ± 8.2** (18) | 134.1 ± 3.4** (15) | 128.0 ± 5.3** (15)
0–3 | 17.6 ± 0.9** (22) | 16.7 ± 1.2 (18) | 16.9 ± 0.7 (20) | 15.7 ± 1.5 (17) | 15.6 ± 0.8 (19) | 16.3 ± 1.4 (18) | 13.0 ± 1.4** (20) | 14.7 ± 1.1 (18) | 11.7 ± 0.9** (15) | 11.4 ± 1.3** (15)
3–6 | 13.8 ± 0.8** (22) | 12.7 ± 0.9** (18) | 13.7 ± 0.7 (20) | 12.9 ± 0.8 (17) | 10.9 ± 0.7** (19) | 10.8 ± 0.6 (18) | 10.4 ± 0.7** (20) | 8.0 ± 1.2** (18) | 9.5 ± 0.4 ** (15) | 8.3 ± 0.5** (15)
6–9 | 13.0 ± 0.6** (22) | 13.2 ± 0.9** (18) | 11.9 ± 0.7 (20) | 11.3 ± 1.1 (17) | 11.7 ± 0.7 (19) | 10.1 ± 0.7* (18) | 9.8 ± 0.7** (20) | 10.1 ± 0.8* (18) | 9.6 ± 0.4 ** (15) | 8.6 ± 0.6** (15)
9–12 | 14.2 ± 0.7** (22) | 13.9 ± 0.8** (18) | 12.9 ± 0.6 (20) | 15.2 ± 1.0 (17) | 10.9 ± 0.5** (19) | 12.2 ± 0.9 (18) | 8.4 ± 1.1** (20) | 10.6 ± 1.1* (18) | 10.7 ± 0.8** (15) | 12.5 ± 0.7 (15)
12–15 | 20.4 ± 0.8** (22) | 21.6 ± 0.9** (18) | 21.1 ± 0.7 (20) | 23.5 ± 1.8 (17) | 18.5 ± 1.0 (19) | 18.0 ± 1.1 (18) | 17.1 ± 0.7* (20) | 18.0 ± 1.5 (18) | 15.6 ± 0.7** (15) | 16.1 ± 0.9** (15)
15–18 | 46.3 ± 1.2** (22) | 47.6 ± 2.4** (18) | 44.3 ± 1.4 (20) | 43.1 ± 1.5 (17) | 40.3 ± 1.7* (19) | 36.4 ± 3.0** (18) | 29.9 ± 2.7** (20) | 31.8 ± 2.6** (18) | 37.5 ± 1.0** (15) | 35.2 ± 2.0** (15)
18–21 | 47.8 ± 2.0** (22) | 42.6 ± 2.3** (18) | 45.9 ± 1.6 (20) | 45.7 ± 2.1 (16) | 41.9 ± 1.7* (19) | 41.2 ± 2.3 (18) | 36.0 ± 1.9** (20) | 33.1 ± 3.3* (18) | 39.1 ± 2.2** (15) | 36.0 ± 1.6* (15)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; EE = ethinyl estradiol; RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Data are displayed as mean ± standard error (n), where n = number of litters. Body weight data are reported in grams.

^c^ Statistical analysis for the RPC performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons. Statistical analysis for the PC performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

#### Gestation Feed Consumption

2H4MBP groups displayed similar absolute feed consumption (g/animal/day) during gestation as the respective control group. Relative feed consumption (g/kg/day) during gestation in the 3,000 and 10,000 ppm 2H4MBP groups was similar to the respective control group (Table 21; Appendix E). Pregnant females in the 30,000 ppm group of the prenatal cohort displayed a significant increase in relative feed consumption between GD 0 and GD 21 (approximately 21%), but this is likely the result of the substantially lower body weights of this group. In the EE group of the reproductive performance cohort, absolute feed consumption between GD 0 and GD 21 was significantly decreased by approximately 19%, and relative feed consumption was similar to that of the control group. The opposite was true for the EE group in the prenatal cohort, in which relative feed consumption was significantly increased by approximately 25% relative to the control group. 2H4MBP intake of both cohorts during gestation, based on feed consumption and dietary concentrations, was approximately 240, 825, and 2,760 mg/kg/day at exposure concentrations of 3,000, 10,000, and 30,000 ppm 2H4MBP, respectively. EE intake was approximately 0.004 mg/kg/day. The respective dose consumed was similar between the two cohorts.

Table 21 Summary of Gestation Feed and Test Article Consumption for F_1_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed^a,b,c^

GD Interval | 0 ppm | | 3,000 ppm | | 10,000 ppm | | 30,000 ppm | | EE 0.05 ppm^d^
GD Interval | RPC | PC | RPC | PC | RPC | PC | RPC | PC | RPC | PC
Feed Consumption (g/animal/day)^e^
0–21 | 27.8 ± 0.8 (22) | 23.5 ± 0.4 (17) | 26.6 ± 0.7 (20) | 22.7 ± 0.6 (13) | 26.1 ± 0.8 (19) | 23.2 ± 0.7 (14) | 25.4 ± 0.6 (19) | 24.1 ± 0.9 (14) | 22.5 ± 0.9** (15) | 23.1 ± 1.4 (14)
0–3 | 26.4 ± 1.7 (22) | 19.7 ± 0.7** (18) | 25.8 ± 1.3 (20) | 20.5 ± 0.9 (17) | 24.9 ± 1.3 (19) | 19.0 ± 0.6 (13) | 26.6 ± 1.1 (18) | 26.3 ± 2.2** (16) | 21.7 ± 1.8* (15) | 24.3 ± 2.9 (13)
3–6 | 25.1 ± 1.4** (22) | 21.2 ± 0.4* (18) | 22.7 ± 0.6 (20) | 20.4 ± 0.5 (17) | 21.2 ± 0.5 (19) | 21.6 ± 1.5 (18) | 19.3 ± 0.5** (18) | 19.3 ± 1.2 (15) | 17.3 ± 0.7** (15) | 16.2 ± 0.5** (14)
6–9 | 30.7 ± 1.3 (22) | 23.8 ± 0.9 (18) | 29.2 ± 1.6 (20) | 21.5 ± 0.8 (15) | 27.5 ± 1.5 (18) | 23.0 ± 1.4 (16) | 31.4 ± 2.0 (17) | 29.1 ± 1.6 (17) | 25.8 ± 2.1* (15) | 26.0 ± 3.2 (14)
9–12 | 22.4 ± 0.4** (22) | 21.6 ± 0.4* (18) | 22.6 ± 0.5 (20) | 21.2 ± 0.6 (17) | 20.7 ± 0.5 (19) | 21.1 ± 1.1 (18) | 19.3 ± 0.6** (19) | 19.6 ± 0.9 (17) | 17.6 ± 0.4** (15) | 17.4 ± 0.3** (15)
12–15 | 31.5 ± 1.0 (22) | 25.2 ± 0.9** (17) | 30.2 ± 1.4 (19) | 23.8 ± 0.6 (15) | 31.9 ± 1.9 (18) | 29.9 ± 2.6 (17) | 35.8 ± 1.8 (18) | 34.3 ± 2.2** (15) | 27.0 ± 2.2* (15) | 28.5 ± 2.6 (15)
15–18 | 26.8 ± 0.5** (22) | 26.6 ± 0.5** (18) | 25.5 ± 0.4 (20) | 25.1 ± 0.5 (17) | 25.0 ± 0.4** (18) | 24.1 ± 1.1** (17) | 21.4 ± 0.8** (20) | 23.3 ± 1.3** (15) | 21.9 ± 0.5** (15) | 28.4 ± 2.9* (15)
18–21 | 31.5 ± 1.0 (22) | 26.6 ± 1.4 (18) | 30.5 ± 1.3 (20) | 27.2 ± 1.2 (16) | 31.4 ± 1.4 (19) | 30.9 ± 2.3 (17) | 30.3 ± 1.5 (20) | 23.6 ± 1.3 (15) | 26.2 ± 1.3** (15) | 24.2 ± 1.4 (15)
Feed Consumption (g/kg/day)^e^
0–21 | 88.5 ± 2.8 (22) | 73.7 ± 1.3** (17) | 84.3 ± 2.1 (20) | 74.7 ± 1.7 (13) | 86.0 ± 2.3 (19) | 79.2 ± 2.5 (14) | 94.8 ± 2.6 (19) | 89.5 ± 3.6** (14) | 88.7 ± 4.6 (15) | 91.9 ± 6.1** (14)
0–3 | 101.0 ± 6.7 (22) | 74.0 ± 2.0** (18) | 98.2 ± 4.9 (20) | 80.3 ± 3.4 (17) | 96.9 ± 4.5 (19) | 77.1 ± 2.5 (13) | 116.9 ± 5.3* (18) | 115.6 ± 9.9** (16) | 102.2 ± 9.9 (15) | 115.0 ± 14.7** (13)
3–6 | 91.4 ± 5.3 (22) | 75.8 ± 1.5 (18) | 81.2 ± 1.7 (20) | 75.4 ± 1.6 (17) | 78.7 ± 2.0 (19) | 83.7 ± 6.4 (18) | 81.2 ± 2.0 (18) | 80.6 ± 4.2 (15) | 76.9 ± 3.7* (15) | 72.7 ± 1.9 (14)
6–9 | 107.4 ± 5.3 (22) | 81.5 ± 3.0** (18) | 101.3 ± 5.7 (20) | 76.8 ± 2.8 (15) | 97.3 ± 4.5 (18) | 84.7 ± 4.5 (16) | 127.0 ± 9.0 (17) | 116.8 ± 7.0** (17) | 112.2 ± 11.6 (15) | 111.7 ± 13.5 (14)
9–12 | 73.7 ± 1.2 (22) | 70.9 ± 1.4 (18) | 74.2 ± 1.3 (20) | 71.4 ± 1.3 (17) | 70.9 ± 1.7 (19) | 74.9 ± 3.9 (18) | 74.2 ± 1.8 (19) | 75.0 ± 3.4 (17) | 71.7 ± 1.0 (15) | 71.8 ± 1.1 (15)
12–15 | 100.2 ± 5.2** (22) | 78.3 ± 3.1** (17) | 95.2 ± 4.7 (19) | 76.8 ± 2.5 (15) | 104.4 ± 5.8 (18) | 100.2 ± 8.6* (17) | 133.8 ± 7.8** (18) | 126.9 ± 9.7** (15) | 106.4 ± 11.0 (15) | 111.8 ± 10.5** (15)
15–18 | 76.0 ± 1.1 (22) | 74.6 ± 1.1 (18) | 72.7 ± 0.8 (20) | 72.9 ± 1.9 (17) | 74.8 ± 1.4 (18) | 73.9 ± 2.8 (17) | 72.9 ± 2.1 (20) | 78.4 ± 4.6 (15) | 77.2 ± 1.4 (15) | 102.1 ± 11.1** (15)
18–21 | 78.9 ± 2.8* (22) | 65.7 ± 3.2 (18) | 76.8 ± 3.6 (20) | 69.6 ± 2.5 (16) | 83.3 ± 3.9 (19) | 86.9 ± 8.3 (17) | 93.8 ± 5.8* (20) | 72.9 ± 5.2 (15) | 82.0 ± 4.8 (15) | 76.4 ± 4.4 (15)
Chemical Intake (mg/kg/day)^f,g^
0–21 | 0.0 ± 0.0 (22) | 0.0 ± 0.0 (17) | 252.8 ± 6.3 (20) | 224.2 ± 5.0 (13) | 859.7 ± 23.2 (19) | 791.8 ± 25.2 (14) | 2,844.2 ± 79.2 (19) | 2,684.4 ± 107.5 (14) | 4.4 ± 0.2^h^ (15) | 4.6 ± 0.3^h^ (14)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; EE = ethinyl estradiol; RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Data are displayed as mean ± standard error (n), where n = number of litters. Consumption is not reported for the nonpregnant animals during gestation and lactation.

^c^ For each dam, calculation of consumption values for the GD 0–21 interval was performed using all valid data for the animal, even if data were unavailable for some of the subintervals.

^d^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^e^ Statistical analysis of the RPC cohort performed using a bootstrapped Jonckheere test for trend, and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons. Statistical analysis of the PC performed using the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^g^ No statistical analysis was performed on the chemical intake data.

^h^ EE intake presented as µg/kg/day.

### Prenatal Cohort Findings

F_1_ rats and F_2_ fetuses from the prenatal cohort were evaluated for maternal reproductive performance and fetal findings, respectively, as shown in Figure 22.

Figure 22

Design of the Modified One-Generation Study – Prenatal Cohort

GD = gestation day; LD = lactation day; PND = postnatal day.

#### Maternal Reproductive Performance and Uterine Data

In the prenatal cohort, females were between 109 and 132 days of age at the time of laparotomy. Pregnant females exposed to 10,000 or 30,000 ppm 2H4MBP displayed lower gravid uterine weights (15% and 17%, respectively), fewer implants, and fewer live fetuses (approximately 2 fewer/litter) than control animals; significant decreases were observed for gravid uterine weight and number of implantations at 30,000 ppm (Table 22). In the 30,000 ppm 2H4MBP group, these findings correlated with significant decreases in the mean number of corpora lutea (approximately 4 fewer/litter) relative to the control group and are consistent with the reduction in live litter size on PND 0 relative to control animals observed in the reproductive performance cohort (Appendix E). Females in the 0.05 ppm EE group exhibited significantly decreased gravid uterine weight (20% lower than the control group), mean number of corpora lutea, implantations, and live fetuses (Table 22). Dams exposed to 2H4MBP or EE did not display any adverse changes in postimplantation loss, mean live fetal weights, or fetal sex ratio.

Table 22 Summary of Uterine Content Data for F_1_ Female Rats in the Prenatal Cohort Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

| 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^a^
Pregnancy Summary^b^
Paired Females | 22 | 20 | 22 | 20 | 15
Mated Females | 19 | 19 | 21 | 19 | 15
Pregnant Females^c^ | 18 | 18 | 20 | 19 | 15
Pregnant Females Examined on GD 21 | 18 | 16 | 18 | 18 | 15
Preimplantation Loss^d,e^
Mean No. of Corpora Lutea/Female | 18.56 ± 0.77** (18) | 17.56 ± 0.77 (18) | 17.40 ± 0.89 (20)^f^ | 14.89 ± 0.87** (19) | 13.53 ± 0.47** (15)
Implantations/Female | 15.61 ± 0.65** (18) | 14.94 ± 0.67 (16) | 13.28 ± 1.17 (18) | 12.94 ± 0.88* (18) | 12.13 ± 0.79** (15)
Preimplantation Loss (%) | 14.51 ± 3.73 (18) | 14.58 ± 3.38 (16) | 24.91 ± 5.80 (18) | 15.89 ± 3.49 (18) | 11.47 ± 4.89 (15)
Intrauterine Deaths^e^
Postimplantation Loss (%)^d,g^ | 5.33 ± 2.38 (18) | 1.85 ± 0.84 (16) | 7.86 ± 3.16 (18) | 8.45 ± 5.46 (18) | 4.19 ± 1.26 (15)
Total Resorptions per Litter^d^ | 0.67 ± 0.26 (18) | 0.31 ± 0.15 (16) | 0.61 ± 0.16 (18) | 0.44 ± 0.12 (18) | 0.53 ± 0.17 (15)
Early Resorptions per Litter^d^ | 0.50 ± 0.25 (18) | 0.31 ± 0.15 (16) | 0.61 ± 0.16 (18) | 0.39 ± 0.12 (18) | 0.47 ± 0.13 (15)
Late Resorptions per Litter^d^ | 0.17 ± 0.09 (18) | 0.00 ± 0.00 (16) | 0.00 ± 0.00 (18) | 0.06 ± 0.06 (18) | 0.07 ± 0.07 (15)
Dead Fetuses per Litter^d^ | 0.00 ± 0.00 (18) | 0.00 ± 0.00 (16) | 0.00 ± 0.00 (18) | 0.00 ± 0.00 (18) | 0.00 ± 0.00 (15)
No. of Early Resorptions | 9 | 5 | 11 | 7 | 7
No. of Late Resorptions | 3 | 0 | 0 | 1 | 1
No. of Whole Litter Resorptions^b^ | 0 | 0 | 0 | 1 | 0
No. of Dead Fetuses | 0 | 0 | 0 | 0 | 0
Live Fetuses^e^
No. of Live Fetuses^g^ | 269 (18) | 234 (16) | 228 (18) | 225 (17) | 174 (15)
Live Fetuses per Litter^d^ | 14.94 ± 0.82 (18) | 14.63 ± 0.59 (16) | 12.67 ± 1.17 (18) | 13.24 ± 0.57 (17) | 11.60 ± 0.76** (15)
Live Male Fetuses per Litter^d^ | 7.83 ± 0.58 (18) | 7.38 ± 0.47 (16) | 6.72 ± 0.74 (18) | 6.76 ± 0.42 (17) | 6.07 ± 0.56* (15)
Live Female Fetuses per Litter^d^ | 7.11 ± 0.76 (18) | 7.25 ± 0.49 (16) | 6.29 ± 0.60 (17) | 6.41 ± 0.54 (17) | 5.53 ± 0.54 (15)
Live Male Fetuses per Litter (%)^d^ | 53.19 ± 3.69 (18) | 50.37 ± 2.60 (16) | 55.21 ± 3.94 (18) | 52.09 ± 3.17 (17) | 51.48 ± 3.59 (15)
Fetal Weight (g)^d,h^
Fetal Weight per Litter | 5.06 ± 0.06 (18) | 5.15 ± 0.09 (16) | 5.08 ± 0.10 (18) | 5.01 ± 0.10 (17) | 5.23 ± 0.08 (15)
Male Fetal Weight per Litter | 5.15 ± 0.07 (18) | 5.34 ± 0.08 (16) | 5.17 ± 0.09 (18) | 5.13 ± 0.10 (17) | 5.37 ± 0.09* (15)
Female Fetal Weight per Litter | 4.95 ± 0.06 (18) | 4.96 ± 0.09 (16) | 4.98 ± 0.11 (17) | 4.89 ± 0.09 (17) | 5.10 ± 0.08 (15)
Gravid Uterine Weight (g)^d,h^
Gravid Uterine Weight | 107.08 ± 5.01** (18) | 107.03 ± 3.26 (16) | 90.65 ± 7.42 (18) | 88.78 ± 6.11* (18) | 85.58 ± 4.96** (15)
Terminal Body Weight | 423.9 ± 7.3** (18) | 412.6 ± 7.1 (16) | 381.6 ± 9.0** (18) | 345.5 ± 9.2** (18) | 335.0 ± 4.8** (15)
Adjusted Body Weight^i^ | 316.82 ± 5.34** (18) | 305.56 ± 5.91 (16) | 290.98 ± 3.02** (18) | 256.75 ± 4.58** (18) | 249.45 ± 3.35** (15)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol; GD = gestation day.

^a^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^b^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^c^ Includes animals that had any evidence of pregnancy but were removed from the study before GD 21.

^d^ Data are reported per litter as mean ± standard error (n) and do not include nonmated, nonpregnant, or unexamined animals or those that did not survive to the end of the study.

^e^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^f^ Includes two dams with total litter loss.

^g^ n = the number of pups examined (number of litters).

^h^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^i^ Body weight adjusted for gravid uterus weight.

#### Fetal Findings

##### Placental Morphology

There was no effect of 2H4MBP or EE exposure on the incidence of placental abnormalities (Appendix E). Fused placentae between two adjacent fetuses were noted for a single litter in the control group and the 10,000 ppm 2H4MBP group. Fused placentae were observed in two litters in the 30,000 ppm 2H4MBP group; one litter had a fusion between two adjacent fetuses, and the other litter had multiple fused placentae. The significant increase in incidence in placental abnormalities in the 30,000 ppm group was not considered 2H4MBP-related as most of the fusions were limited to a single litter and fused placentae have been observed in control litters of different stocks of Sprague Dawley rats.

##### External

There was no effect of 2H4MBP or EE at the exposures tested on the incidence of fetal external abnormalities (Appendix E), which were limited to a single fetus in the 30,000 ppm group that displayed anal atresia, clubbed hind limbs, tail agenesis, and a hematoma on the torso. This fetus also had multiple visceral and skeletal abnormalities.

##### Visceral

Male and female fetuses (combined) exposed to 30,000 ppm 2H4MBP displayed a higher incidence of enlarged liver, a malformation (Table 23), which had not been observed in NTP historical controls.

Table 23 Summary of Select Visceral Findings in Fetuses Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

| 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^a^
No. Litters Examined | 18 | 16 | 18 | 17 | 15
No. Fetuses Examined | 269 | 234 | 228 | 225 | 174
Fetal Findings^b,c^
Enlarged liver – [M]^d^
Fetuses | 0 (0.0) | 1 (0.43) | 2 (0.88) | 7 (3.11) | 0 (0.0)
Litters | 0 (0.00) | 1 (6.25) | 1 (5.56) | 2 (11.76) | 0 (0.00)
Hydronephrosis – [M]^e^
Fetuses | 3 (1.12) | 1 (0.43) | 0 (0.0) | 5 (2.22) | 2 (1.15)
Litters | 3 (16.67) | 1 (6.25) | 0 (0.00) | 5(29.41) | 2 (13.33)
Distended ureter, bilateral – [V]^f^
Fetuses | 4 (1.49) | 11 (4.7) | 15 (6.58)^#^ | 10 (4.44) | 12 (6.9)^#^
Litters | 3 (16.67) | 6 (37.50) | 8 (44.44) | 5 (29.41) | 7 (46.67)
Distended ureter – [V]^g^
Fetuses | 13 (4.83) | 25 (10.68) | 29 (12.72) | 19 (8.44) | 22 (12.64)
Litters | 8 (44.44) | 10 (62.50) | 9 (50.00) | 6 (35.29) | 7 (46.67)
Ventricular septum, septum defect – [M]^h^
Fetuses | 0 (0.0) | 0 (0.0) | 2 (0.88) | 1 (0.44) | 0 (0.0)
Litters | 0 (0.00) | 0 (0.00) | 2 (11.11) | 1 (5.88) | 0 (0.00)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

^#^ Statistically significant at p ≤ 0.05 (litter-based analysis).

EE = ethinyl estradiol; [M] = malformation; [V] = variation.

^a^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^b^ Upper row denotes number of affected fetuses (%) and lower row the number of affected litters (%).

^c^ Statistical analysis for fetal data including litter effects performed using a Rao-Scott modification to the Cochran-Armitage test where the litter was the random effect for both trend and pairwise analyses.

^d^ Historical control incidence: fetuses – 0/1,385; litters – 0/97.

^e^ Historical control incidence: fetuses – 4/1,385 (0.29%), range 0.00% to 0.81%; litters – 4/97 (4.12%), range 0.00% to 16.67%.

^f^ Historical control incidence: fetuses – 60/1,385 (4.33%), range 1.28% to 7.85%; litters – 28/97 (28.87%), range 12.50% to 43.18%.

^g^ Historical control incidence: fetuses – 151/1,385 (10.90%), range 4.83% to 15.36%; litters – 55/97 (56.70%), range 43.75% to 68.18%.

^h^ Historical control incidence: fetuses – 1/1,385 (0.07%), range 0.00% to 0.17%; litters – 1/97 (1.03%), range 0.00% to 2.27%.

The 30,000 ppm 2H4MBP group displayed a higher incidence of unilateral or bilateral (combined) hydronephrosis, a malformation, relative to the control group (Table 23). This higher incidence was observed in 2.22% of the fetuses (29.41% of the litters), whereas it was observed in 1.12% and 1.15% of the fetuses (16.67% and 13.33% of the litters) from the control group and EE group, respectively. The NTP historical control range for unilateral or bilateral hydronephrosis is 0.00% to 0.81% for fetuses; (0.00% to 16.67% for litters). The incidence of bilateral distended ureter, a variation, was higher in all 2H4MBP-exposed groups as well as the EE group, relative to the control group. When unilateral and bilateral distended ureters were combined, the fetal incidence was 10.68%, 12.72%, and 8.44% (62.50%, 50.00%, and 35.29% of the litters) in the 3,000, 10,000, and 30,000 ppm groups versus 4.83% and 12.64% (44.44% and 46.67% of the litters) in the control and EE groups, respectively. Historical control incidence for distended ureter in fetuses is 10.90% (4.83% to 15.36%) and for litters is 56.70% (43.75% to 68.18%). Hydroureter of the left kidney was observed in one fetus in the control group and in two fetuses in the 3,000 ppm group, but given the low incidence, these were not considered related to 2H4MBP exposure (Appendix E). The NTP historical control range for hydroureter is up to 2.83% and 21.05% for fetuses and litters, respectively. Hydronephrosis and other abnormalities associated with the kidney and ureter (e.g., dilated renal pelvis, distended ureter, hydroureter) are common findings in this strain of rat; therefore, these collective findings may or may not be related to the 2H4MBP-associated microscopic findings observed in the kidney of adult F_1_ males and females exposed to 30,000 ppm 2H4MBP (Appendix E).

Other malformations observed in 2H4MBP-exposed fetuses include ventricular septal defects in two fetuses in the 10,000 ppm group and in one fetus in the 30,000 ppm group (Table 23). This finding was not considered related to 2H4MBP due to the low incidence and lack of a clear exposure concentration-response and because it had been observed in a control fetus in a previous study (1/1,385). A single fetus (dam 1950, fetus 01) in the 30,000 ppm 2H4MBP group displayed adrenal gland agenesis, malpositioned kidneys, distended stomach, and agenesis of the gonads (Appendix E). This fetus also had external and skeletal malformations. None of the visceral findings associated with this fetus was considered 2H4MBP-related due to their singular occurrence. One fetus in the 10,000 ppm group displayed small, round kidneys, which were not considered 2H4MBP-related due to the singular occurrence.

There were no additional effects of EE exposure on the incidence of fetal visceral variations.

##### Head

There was no effect of 2H4MBP or EE exposure on the incidence of fetal head abnormalities at the exposures tested. Fetal head abnormalities were limited to a single fetus in the 3,000 ppm group that displayed anophthalmia of the right eye (Appendix E).

##### Skeletal

There was no effect of 2H4MBP or EE exposure on the incidence of fetal skeletal abnormalities at the exposures tested (Appendix E). Skeletal malformations in exposed groups were limited to fused sternebrae, multiple rib abnormalities, and vertebral abnormalities in a single fetus in the 30,000 ppm 2H4MBP group. Full lumbar 1 ribs were observed in several fetuses in the 3,000 and 10,000 ppm 2H4MBP groups. Given the low incidence and lack of an exposure response, these findings were not considered 2H4MBP-related.

Skeletal variations observed in 2H4MBP- and/or EE-exposed groups included incomplete ossification of the parietal skull, sternebrae extra ossification sites, misaligned sternebrae, incomplete sternebrae ossification (II, III, IV, V, VI), rudimentary rib (lumbar 1), thoracic centrum bipartite ossification, and thoracic centrum dumbbell ossification. With the exception of the lumbar 1 rudimentary rib variation, the incidences of the variations were limited to <3 fetuses per group. The incidences of the skeletal variations were not considered related to the test article because there was no exposure-related trend and/or the incidences were similar to the concurrent control group (Appendix E).

### Reproductive Performance Cohort Findings

F_1_ and F_2_ rats from the reproductive performance cohort were evaluated for maternal reproductive performance and offspring effects, respectively, as shown in Figure 23. Littering, mean body weights, and feed consumption results from the F_1_ rats as well as viability, clinical observations, mean body weights, and gross pathology results from the F_2_ rats are presented below.

Figure 23

Design of the Modified One-Generation Study – Reproductive Performance Cohort

GD = gestation day; LD = lactation day; PND = postnatal day.

#### Reproductive Performance and Littering

Reproductive performance and littering parameters for the reproductive performance cohort are presented in Table 24. Gestation length was similar among the 2H4MBP-exposed groups and the control group. The EE group displayed a significant decrease (approximately 0.4 days) in gestation length compared to the control group.

Table 24 Summary of Reproductive Parameters of F_1_ Female Rats in the Reproductive Performance Cohort Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

| 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^a^
No. Females Paired | 41 | 40 | 40 | 40 | 30
No. Females Mated | 40 | 37 | 35 | 35 | 29
No. Females Littering | 35 | 37 | 33 | 32 | 28
Percent of Mated Females/Paired^b,c^ | 97.6 | 92.5 | 87.5 | 87.5 | 96.7
Percent of Littered Females/Paired^b,c^ | 85.4 | 92.5 | 82.5 | 80.0 | 93.3
Percent of Littered Females/Mated^b,c^ | 87.5 | 100.0 | 94.3 | 91.4 | 96.6
Precoital Interval (days)^d,e,f^ | 4.7 ± 0.6 (22) | 4.8 ± 0.5 (20) | 5.1 ± 0.7 (19) | 4.2 ± 0.8 (20) | 4.0 ± 0.6 (15)
Gestation Length (days)^d,e,g^ | 22.4 ± 0.1 (22) | 22.5 ± 0.1 (20) | 22.6 ± 0.1 (19) | 22.2 ± 0.1 (20) | 22.0 ± 0.1** (15)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

** Statistically significant at p ≤ 0.01.

EE = ethinyl estradiol.

^a^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^b^ Statistical analysis performed using the Rao-Scott Cochran-Armitage test for both trend and pairwise comparisons to adjust for litter effects (unless otherwise noted).

^c^ Animals removed from the study between mating and littering were excluded from calculations of percent littered females.

^d^ Statistical analysis performed using a bootstrapped Jonckheere test for trend, and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

^e^ Data are displayed as mean ± standard error (n).

^f^ Precoital interval calculated for sperm-positive females.

^g^ Gestation length calculated for sperm-positive females that delivered a litter.

#### Lactation Body Weights and Feed Consumption

Consistent with their premating and gestation weights, F_1_ female mean body weights during lactation were significantly decreased in the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups relative to the control group (Table 25; Figure 24). On LDs 1 and 28, female mean body weights of the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups were significantly decreased by 5%–7%, 18%–20%, and 19%–21%, respectively, compared to the control group. Body weight gain between LD 1 and LD 28 in the 10,000 and 30,000 ppm 2H4MBP and 0.05 ppm EE groups was higher relative to the control group. In general, feed consumption (g/animal/day) during lactation in the groups exposed to 2H4MBP or EE were similar to the control group (Table 25). 2H4MBP intake during lactation in the 3,000, 10,000, and 30,000 ppm 2H4MBP groups, based on feed consumption and dietary concentrations for the LD 1–13 interval, was approximately 426, 1,621, and 5,944 mg/kg/day, respectively (Table 25). EE intake during the postweaning period was approximately 0.009 mg/kg/day.

Table 25 Summary of Mean Body Weights, Body Weight Gains, and Feed and Test Article Consumption for F_1_ Female Rats in the Reproductive Performance Cohort Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed during Lactation

Lactation Day^a^ | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^b^
Body Weight (g)^c^
1 | 309.2 ± 6.0** (22) | 309.4 ± 4.1 (20) | 288.3 ± 4.7* (20) | 248.1 ± 5.7** (20) | 243.6 ± 4.9** (15)
13 | 333.9 ± 5.4** (22) | 333.4 ± 4.2 (20) | 310.8 ± 4.2** (20) | 263.4 ± 5.1** (20) | 272.0 ± 4.5** (15)
28 | 317.8 ± 5.1** (22) | 316.4 ± 4.0 (20) | 300.9 ± 3.9* (20) | 260.9 ± 4.0** (20) | 255.9 ± 4.7** (15)
Body Weight Gain (g)^c^
1–28 | 8.6 ± 2.9 (22) | 7.0 ± 2.7 (20) | 12.6 ± 3.2 (20) | 12.8 ± 4.0 (20) | 12.3 ± 2.5 (15)
Feed Consumption^d^
1–13 (g/animal/day) | 44.8 ± 1.1* (21) | 45.9 ± 1.3 (20) | 48.6 ± 1.7 (20) | 50.4 ± 2.1 (20) | 45.6 ± 1.6 (15)
1–13 (g/kg/day) | 139.1 ± 3.5** (21) | 142.1 ± 4.5 (20) | 162.1 ± 6.0** (20) | 198.1 ± 9.0** (20) | 177.1 ± 8.4** (15)
Chemical Intake (mg/kg/day)^e,f^
1–13 | 0.0 ± 0.0 (21) | 426.2 ± 13.5 (20) | 1,620.8 ± 60.0 (20) | 5,944.0 ± 268.8 (20) | 8.9 ± 0.4 (15)^g^

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol.

^a^ Data are displayed as mean ± standard error (n), where n = number of litters.

^b^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^c^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple comparisons.

^d^ Statistical analysis performed using a bootstrapped Jonckheere test for trend, and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

^e^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^f^ No statistical analysis performed on the chemical intake data.

^g^ EE consumption presented as µg/kg/day.

Figure 24

Lactation Growth Curves for F_1_ Female Rats in the Reproductive Performance Cohort Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

EE = ethinyl estradiol. Information for statistical significance in F_1_ female rat weights is provided in Table 25.

#### F_2_ Viability and Clinical Observations

Clinical observations noted in individual pups in all groups, including the control group, were typically indicative of an individual pup not thriving (e.g., cold to the touch, no milk in the stomach). Exposure-related reductions in mean total and live litter size were observed in the 2H4MBP- and EE-exposed groups. Dams in the 10,000 and 30,000 ppm 2H4MBP groups had lower total and live litter size than the control group on PND 0 (by ~1 pup/litter). PND 0 total and live litter sizes in the EE-exposed group were significantly decreased (by ~2 pups/litter) relative to the control group (Table 26). Although the reductions in mean live litter size in the 2H4MBP-exposed groups did not achieve statistical significance compared to the control group after PND 0, the findings were consistent with the reductions in the mean number of live fetuses/pregnant females that were observed in the prenatal cohort (Table 22).

Table 26 Summary of F_2_ Litter Size and Pup Survival Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone

Postnatal Day | 0 ppm | | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^a^
No. of Live Pups (Litters)^b^
0 | 477 (35) | 462 (37) | | 404 (33) | 386 (32) | 314 (28)
Total Litter Size^c,d^
0 | 14.6 ± 0.5* (22) | 13.8 ± 0.5 (20) | | 13.7 ± 0.7 (20) | 12.9 ± 0.5* (20) | 11.8 ± 0.4** (15)
Live Litter Size^c,d^
0 | 13.6 ± 0.5* (22) | 12.9 ± 0.6 (20) | | 12.4 ± 0.9 (20) | 12.0 ± 0.4* (20) | 11.3 ± 0.5** (15)
1 | 13.4 ± 0.5* (22) | 12.7 ± 0.6 (20) | | 12.2 ± 0.9 (20) | 12.0 ± 0.4 (20) | 10.9 ± 0.5** (15)
4 (prestandardization) | 13.1 ± 0.4* (22) | 12.6 ± 0.6 (20) | | 11.9 ± 0.8 (20) | 11.5 ± 0.4 (20) | 10.8 ± 0.5** (15)
4 (poststandardization) | 7.8 ± 0.2 (22) | 7.6 ± 0.2 (20) | | 7.6 ± 0.3 (20) | 7.9 ± 0.1 (20) | 7.6 ± 0.2 (15)
7 | 6.8 ± 0.4 (21) | 6.9 ± 0.3 (20) | | 6.8 ± 0.3 (20) | 6.8 ± 0.4 (20) | 7.3 ± 0.3 (15)
13 | 5.7 ± 0.4 (20) | 6.1 ± 0.3 (19) | | 5.8 ± 0.3 (20) | 6.2 ± 0.4 (18) | 6.8 ± 0.3* (15)
21 | 5.7 ± 0.4 (20) | 5.9 ± 0.3 (19) | | 5.7 ± 0.3 (20) | 6.0 ± 0.4 (18) | 6.8 ± 0.3* (15)
28 | 5.7 ± 0.4 (20) | 5.9 ± 0.3 (19) | | 5.7 ± 0.3 (20) | 5.9 ± 0.3 (18) | 6.7 ± 0.3* (15)
No. of Dead Pups (Litters)^c,d^
0 | 34 (18) | 41 (13) | | 42 (18) | 29 (17) | 16 (12)
1–4 | 27 (13) | 13 (9) | | 17 (9) | 13 (11) | 14 (8)
5–28 | 83 (26) | 69 (25) | | 58 (23) | 79 (24) | 35 (13)
Dead per Litter^c,d^
0 | 0.95 ± 0.27 (22) | 1.03 ± 0.49 (20) | | 1.67 ± 0.70 (20) | 0.94 ± 0.25 (20) | 0.47 ± 0.15 (15)
1–4 | 0.84 ± 0.32 (22) | 0.35 ± 0.12 (20) | | 0.45 ± 0.13 (20) | 0.48 ± 0.16 (20) | 0.53 ± 0.19 (15)
5–28 | 2.73 ± 0.45 (22) | 1.93 ± 0.40 (20) | | 1.84 ± 0.29 (20) | 2.60 ± 0.51 (20) | 1.18 ± 0.28** (15)
Survival Ratio^c,d^
0 | 0.94 ± 0.02 (22) | 0.94 ± 0.03 (20) | | 0.86 ± 0.05 (20) | 0.93 ± 0.02 (20) | 0.95 ± 0.02 (15)
1–4 | 0.92 ± 0.03 (22) | 0.98 ± 0.01 (20) | | 0.97 ± 0.01 (20) | 0.96 ± 0.01 (20) | 0.95 ± 0.02 (15)
5–28 | 0.68 ± 0.06 (22) | 0.75 ± 0.05 (20) | | 0.77 ± 0.04 (20) | 0.67 ± 0.06 (20) | 0.85 ± 0.04** (15)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol.

^a^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^b^ n = the number of pups examined (number of F_1_ litters).

^c^ Data are displayed as the mean of litter values ± standard error of litter values (n = number of litters produced by F_0_ dams); n is dependent on the number of litters produced by the F_0_ generation in which up to two nonindependent F_1_ offspring/sex/litter were selected to produce F_2_ pups through nonsibling mating.

^d^ Statistical analysis performed using a bootstrapped Jonckheere test for trend, and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

#### F_2_ Body Weights

##### Male Pups

Male pups exposed to 30,000 ppm 2H4MBP displayed lower mean body weights (litter means) over time compared to the control group (Table 27; Figure 25; Appendix E). On PND 21, male pup mean body weights per litter of the 30,000 ppm group were lower by approximately 8% and by PND 28 they were significantly decreased 14% relative to the control group. A significant decrease in pup mean body weight was first observed in male offspring on PND 25 (Appendix E). These effects are consistent with what was observed in the F_1_ generation, but the magnitude of change with exposure concentration is not as severe. EE exposure had no adverse effect on male pup mean body weights.

Table 27 Summary of F_2_ Male and Female Pup Mean Body Weights and Body Weight Gains Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone^a,b^

Postnatal Day | 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.05 ppm^c^
Male
Body Weight
1 | 6.87 ± 0.12 213 (33)^d^ | 7.09 ± 0.14 226 (36) | 6.99 ± 0.14 192 (32) | 6.67 ± 0.09 185 (32) | 6.47 ± 0.10** 144 (28)
4 | 9.02 ± 0.24 205 (33) | 9.55 ± 0.30 223 (36) | 9.56 ± 0.25 187 (32) | 8.71 ± 0.16 184 (32) | 9.09 ± 0.18 141 (28)
21 | 42.64 ± 1.28** 91 (30) | 47.80 ± 1.32** 110 (34) | 46.03 ± 1.10 101 (32) | 39.26 ± 1.33 88 (30) | 46.22 ± 0.95* 88 (27)
28 | 72.36 ± 1.90** 91 (30) | 80.50 ± 2.01** 110 (34) | 75.48 ± 1.76 101 (32) | 61.89 ± 2.46** 88 (30) | 76.68 ± 1.19 87 (27)
Body Weight Gain
4–28 | 63.04 ± 1.77** 91 (30) | 70.29 ± 1.79* 110 (34) | 65.61 ± 1.56 101 (32) | 52.51 ± 2.38** 88 (30) | 66.84 ± 1.09 87 (27)
Female
Body Weight
1 | 6.55 ± 0.13** 255 (35) | 6.79 ± 0.12 230 (35) | 6.41 ± 0.13 207 (32) | 6.25 ± 0.09 199 (32) | 6.14 ± 0.10** 160 (27)
4 | 8.48 ± 0.24* 245 (34) | 8.92 ± 0.28 226 (35) | 8.38 ± 0.24 200 (32) | 8.05 ± 0.18 190 (32) | 8.18 ± 0.20 159 (27)
21 | 42.44 ± 1.23** 94 (30) | 43.03 ± 1.31 95 (32) | 41.98 ± 1.13 85 (32) | 37.53 ± 1.27** 87 (28) | 44.05 ± 0.82 91 (26)
28 | 68.94 ± 1.70** 94 (30) | 70.31 ± 1.96 95 (32) | 66.00 ± 1.70 85 (32) | 54.31 ± 2.09** 86 (28) | 71.09 ± 1.03 91 (26)
Body Weight Gain
4–28 | 59.94 ± 1.50** 94 (30) | 60.98 ± 1.81 95 (32) | 57.01 ± 1.57 85 (32) | 45.47 ± 1.93** 86 (28) | 61.74 ± 0.97 91 (26)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol.

^a^ Data are displayed as mean ± standard error of the litter means. Body weight data are presented in grams.

^b^ Statistical analysis performed using mixed effects models with litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons. Pup weights were adjusted for covariate litter size: total live on postnatal day 1 for day 1 to day 4 and number of live pups poststandardization for later days.

^c^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^d^ n = number of pups examined (number of F_1_ litters).

Figure 25

Lactation Growth Curves for F_2_ Male Pups Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone

EE = ethinyl estradiol. Information for statistical significance in F_2_ male rat weights is provided in Table 27.

##### Female Pups

Female pups exposed to 30,000 ppm 2H4MBP also displayed lower mean body weights (litter means) relative to the control group (Table 27; Figure 26; Appendix E). On PND 21 and PND 28, female pup mean body weights per litter of the 30,000 ppm group were significantly decreased by approximately 12% and 22% relative to the control group, respectively. A significant decrease in pup mean body weight was first observed in female offspring on PND 19 (Appendix E). These effects are consistent with what was observed in the F_1_ generation, but the magnitude of reduction with exposure concentration is not as severe. There was no adverse effect of EE exposure on female pup mean body weights.

Figure 26

Lactation Growth Curves for F_2_ Female Pups Following Perinatal Exposure to 2-Hydroxy-4-methoxybenzophenone

EE = ethinyl estradiol. Information for statistical significance in F_2_ female rat weights is provided in Table 27.

### Prenatal and Reproductive Performance Cohorts: Necropsies

#### F_1_ Male Necropsies

F_1_ males in the reproductive performance cohort were euthanized following the mating period at 153–155 days of age. The F_1_ males in the prenatal cohort were euthanized following completion of pairing at 111–113 days of age.

Male rats exposed to 30,000 ppm 2H4MBP displayed a higher incidence of discolored (pale or dark) or enlarged kidneys and discolored (brown) urinary bladders (Table 28). Necropsy mean body weights of rats exposed to 30,000 ppm 2H4MBP or 0.05 ppm EE in both cohorts were significantly decreased by 14% and 15%−20%, respectively, compared to control animals (Table 29). Rats in both cohorts from all 2H4MBP-exposed groups displayed higher left and right absolute and relative kidney weights (Table 29). Absolute kidney weights were 5%−12%, 12%−14%, and 13%−22% higher and relative weights were 7%−10%, 15%−16%, and 30%−42% higher than those of control animals in the 3,000, 10,000, and 30,000 ppm groups, respectively. Gross findings in the kidney and bladder correlated with histopathological changes consistent with a retrograde nephropathy. One male rat in the 30,000 ppm 2H4MBP group in the reproductive performance cohort exhibited a diaphragmatic hernia. These hernias were also observed in F_1_ females and in the F_2_ generation. One male in the 30,000 ppm 2H4MBP group displayed hypospadias and another displayed bilateral smaller testes (Appendix E).

Table 28 Summary of Gross Necropsy Findings in Adult F_1_ Male Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed^a^

| 0 ppm | | 3,000 ppm | | 10,000 ppm | | 30,000 ppm | | EE 0.05 ppm
| RPC | PC | RPC | PC | RPC | PC | RPC | PC | RPC | PC
No. of Animals Examined (No. of Litters) | 41 (22) | 23 (22) | 40 (20) | 20 (20) | 40 (21) | 22 (21) | 40 (20) | 20 (20) | 30 (15) | 15 (15)
Kidney^b^
Dilation
Unilateral | 1 (1) | 0 | 0 | 0 | 0 | 2 (2) | 1 (1) | 0 | 0 | 0
Enlarged
Unilateral | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 (1) | 0 | 0
Bilateral | 0 | 0 | 0 | 0 | 1 (1) | 0 | 1 (1) | 5 (5) | 0 | 0
Discolored, dark
Unilateral | 0 | 0 | 0 | 0 | 0 | 0 | 4 (4) | 0 | 0 | 0
Bilateral | 0 | 0 | 0 | 0 | 0 | 0 | 15 (12) | 4 (4) | 0 | 0
Unilateral or bilateral | 0 | 0 | 0 | 0 | 0 | 0 | 19 (14) | 4 (4) | 0 | 0
Discolored, pale
Unilateral | 0 | 0 | 0 | 0 | 0 | 0 | 4 (4) | 4 (4) | 0 | 0
Bilateral | 0 | 0 | 0 | 0 | 0 | 0 | 1 (1) | 0 | 0 | 0
Unilateral or bilateral | 0 | 0 | 0 | 0 | 0 | 0 | 5 (5) | 4 (4) | 0 | 0
Discolored, mottled
Unilateral | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
Bilateral | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 (1) | 0 | 0
Unilateral or bilateral | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 1 (1) | 0 | 0
Urinary Bladder^b^
Discoloration, brown | 0 | 0 | 0 | 0 | 0 | 0 | 16 (14) | 9 (9) | 0 | 0

EE = ethinyl estradiol; RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Incidence presented as number of animals with lesion (number of litters). No statistical analysis was performed.

Table 29 Summary of Organ Weights of Adult F_1_ Male Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed^a,b,c^

| 0 ppm | | 3,000 ppm | | 10,000 ppm | | 30,000 ppm | | EE 0.05 ppm^d^
| RPC | PC | RPC | PC | RPC | PC | RPC | PC | RPC | PC
No. of Litters Examined | 22 | 23 | 20 | 20 | 21 | 22 | 20 | 20 | 15 | 15
Necropsy Body Wt. (g) | 485.5 ± 5.0** | 422.3 ± 6.6** | 478.5 ± 4.6 | 430.9 ± 7.1 | 468.3 ± 5.2 | 414.2 ± 5.0 | 419.6 ± 6.9** | 365.1 ± 5.4** | 389.5 ± 6.2** | 353.8 ± 5.8**
Liver
Absolute (g) | 18.25 ± 0.30** | 18.80 ± 0.50** | 19.29 ± 0.32 | 20.81 ± 0.42** | 21.19 ± 0.35** | 22.58 ± 0.49** | 21.09 ± 0.34** | 21.41 ± 0.32** | 15.41 ± 0.29** | 15.70 ± 0.46**
Relative (mg/g)^e^ | 37.55 ± 0.35** | 44.43 ± 0.67** | 40.27 ± 0.44** | 48.36 ± 0.76** | 45.24 ± 0.52** | 54.49 ± 0.91** | 50.37 ± 0.52** | 58.72 ± 0.69** | 39.56 ± 0.47** | 44.34 ± 0.91
R. Kidney
Absolute (g) | 1.65 ± 0.02** | 1.57 ± 0.04** | 1.74 ± 0.03 | 1.71 ± 0.02** | 1.84 ± 0.03** | 1.76 ± 0.04** | 2.02 ± 0.04** | 1.77 ± 0.05** | 1.41 ± 0.02** | 1.35 ± 0.02**
Relative (mg/g) | 3.41 ± 0.04** | 3.71 ± 0.07** | 3.64 ± 0.04* | 3.99 ± 0.06* | 3.92 ± 0.05** | 4.25 ± 0.07** | 4.84 ± 0.10** | 4.85 ± 0.13** | 3.64 ± 0.04** | 3.82 ± 0.07
L. Kidney
Absolute (g) | 1.65 ± 0.02** | 1.53 ± 0.04** | 1.74 ± 0.03 | 1.72 ± 0.03** | 1.84 ± 0.04** | 1.74 ± 0.04** | 2.01 ± 0.04** | 1.73 ± 0.04** | 1.42 ± 0.02** | 1.34 ± 0.02**
Relative (mg/g) | 3.39 ± 0.04** | 3.63 ± 0.06** | 3.64 ± 0.04 | 4.01 ± 0.11** | 3.93 ± 0.06** | 4.19 ± 0.07** | 4.82 ± 0.11** | 4.73 ± 0.07** | 3.65 ± 0.06** | 3.79 ± 0.07
R. Testis
Absolute (g) | 2.10 ± 0.02** | 1.95 ± 0.04** | 2.08 ± 0.02 | 2.03 ± 0.03 | 1.98 ± 0.03* | 1.91 ± 0.03 | 1.98 ± 0.04* | 1.87 ± 0.03 | 1.92 ± 0.03** | 1.87 ± 0.04
L. Testis
Absolute (g) | 2.10 ± 0.02** | 1.97 ± 0.03** | 2.07 ± 0.02 | 2.03 ± 0.03 | 1.98 ± 0.03** | 1.91 ± 0.04 | 1.98 ± 0.03** | 1.86 ± 0.03* | 1.92 ± 0.02** | 1.87 ± 0.03*
R. Epididymis
Absolute (g) | 0.69 ± 0.01** | 0.65 ± 0.01 | 0.69 ± 0.01 | 0.66 ± 0.01 | 0.66 ± 0.01 | 0.62 ± 0.01 | 0.66 ± 0.01* | 0.63 ± 0.01 | 0.64 ± 0.01** | 0.61 ± 0.01
L. Epididymis
Absolute (g) | 0.70 ± 0.01** | 0.65 ± 0.01 | 0.68 ± 0.01 | 0.67 ± 0.01 | 0.67 ± 0.01 | 0.63 ± 0.01 | 0.65 ± 0.01** | 0.62 ± 0.01 | 0.64 ± 0.01** | 0.61 ± 0.02*
Seminal Vesicles with Coagulating Gland^f^
Absolute (g) | 1.51 ± 0.04 | 1.49 ± 0.05 | 1.50 ± 0.04 | 1.53 ± 0.06 | 1.45 ± 0.04 | 1.44 ± 0.04 | 1.42 ± 0.03 | 1.44 ± 0.05 | 1.33 ± 0.05* | 1.34 ± 0.05
Dorso-lateral Prostate
Absolute (g) | 0.45 ± 0.01** | 0.49 ± 0.02 | 0.47 ± 0.02 | 0.47 ± 0.03 | 0.45 ± 0.02 | 0.50 ± 0.02 | 0.40 ± 0.02 | 0.43 ± 0.02 | 0.41 ± 0.01 | 0.40 ± 0.02**
Ventral Prostate
Absolute (g) | 0.74 ± 0.02** | 0.57 ± 0.03 | 0.74 ± 0.02 | 0.54 ± 0.03 | 0.66 ± 0.02* | 0.54 ± 0.02 | 0.60 ± 0.02** | 0.52 ± 0.02 | 0.67 ± 0.03 | 0.52 ± 0.02
Levator Ani/bulbocavernosus Muscle Complex
Absolute (g) | 1.24 ± 0.02** | 1.25 ± 0.03** | 1.21 ± 0.02 | 1.24 ± 0.03 | 1.18 ± 0.02 | 1.12 ± 0.03* | 1.09 ± 0.03** | 1.13 ± 0.03** | 1.08 ± 0.02** | 1.14 ± 0.03*
Relative (mg/g) | 2.56 ± 0.04 | 2.96 ± 0.06 | 2.54 ± 0.03 | 2.88 ± 0.09 | 2.53 ± 0.03 | 2.77 ± 0.06 | 2.61 ± 0.05 | 3.09 ± 0.08 | 2.78 ± 0.05** | 3.23 ± 0.07**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol; RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in (Appendix E).

^b^ Data are displayed as mean ± standard error of the litter means.

^c^ Statistical analysis for the RPC performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests. Statistical analysis for the PC performed using mixed models with a random effect for litter and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^d^ The EE group was not included in any trend analysis, it was included in the pairwise analysis to the vehicle control group.

^e^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

^f^ For the PC, n = 22, 19, 20, and 16 litters for the 0, 3,000, 10,000, and 30,000 ppm groups, respectively. For the RPC, n = 19 litters for the 3,000 ppm group.

Male rats in all 2H4MBP-exposed groups in both cohorts displayed higher absolute and relative liver weights compared to the control animals (Table 29). Absolute liver weights of males exposed to 3,000 ppm 2H4MBP in the reproductive performance and prenatal cohorts were higher by 6% and 11%, respectively, relative to control animals. Absolute liver weights of males in both cohorts exposed to 10,000 and 30,000 ppm were significantly increased 14%−20% relative to control animals. Relative liver weights of the 3,000, 10,000, and 30,000 ppm 2H4MBP groups in both cohorts were significantly increased approximately 7%−9%, 20%−23%, and 32%−34%, respectively, relative to the control group. The reproductive performance and prenatal cohorts displayed generally similar responses.

Rats in both cohorts exposed to 30,000 ppm 2H4MBP displayed slightly lower right and left absolute testis weights (approximately 4%−6%) (Table 29). Rats exposed to 30,000 ppm in the reproductive performance cohort exhibited a slight but significant decrease (5%−6%) in right and left absolute epididymis weights. Absolute ventral prostate gland weights of the 30,000 ppm 2H4MBP groups were lower by 19% and 9% relative to control animals in the reproductive performance and prenatal cohorts, respectively. This difference in cohort response might be due to duration of exposure being longer in the reproductive performance cohort. No 2H4MBP-related histopathological effects in the testis or epididymis were found. No exposure-related changes in sperm motility, sperm concentration, or testicular sperm head concentration were found (Appendix E). Rats in the 30,000 ppm 2H4MBP group in both cohorts displayed significantly decreased absolute levator ani/bulbocavernosus (LABC) muscle weights (10%−12%); however, when adjusted for body weight, this difference was negligible (Table 29). No gross pathological findings in the males exposed to 0.05 ppm EE were considered to be related to exposure. In general, male rats exposed to EE displayed lower absolute weights of the testes, epididymides, prostate gland, kidney, liver, seminal vesicles with coagulating glands, and LABC. These observations are likely the result of exposed animals weighing 15%−20% less than control animals.

#### F_1_ Female Necropsies

F_1_ females (and F_2_ offspring) in the reproductive performance cohort were euthanized and necropsied on PND 28, when the F_1_ females were between 127 and 168 days of age. F_1_ females in the prenatal cohort were between 109 and 132 days of age at the time of necropsy and the collection of organ weight data.

There were no gross observations in the prenatal cohort attributed to 2H4MBP exposure. Females in the reproductive performance cohort exposed to 30,000 ppm 2H4MBP displayed a higher individual and litter incidence of abnormal kidney findings (dilation, discoloration) (Table 30). These findings were also observed at a low incidence in the 3,000 ppm group and are consistent with what was observed in the F_1_ males. This difference in response between the two cohorts might have been the result of duration of exposure and is consistent with what was observed in the F_1_ males.

Table 30 Summary of Gross Necropsy Findings in Adult F_1_ Female Rats in the Reproductive Performance Cohort Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

| 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.5 ppm
No. of Animals Examined (No. of Litters) | 41 (22) | 40 (20) | 40 (21) | 40 (20) | 30 (15)
Kidney^a^
Dilation
Unilateral | 0 | 1 (1) | 0 | 2 (2) | 0
Enlarged
Unilateral | 0 | 0 | 0 | 1 (1) | 0
Discolored, dark
Unilateral | 0 | 0 | 0 | 1 (1) | 0
Bilateral | 0 | 0 | 0 | 1 (1) | 0
Unilateral or bilateral | 0 | 0 | 0 | 2 (2) | 0
Discolored, pale
Unilateral | 0 | 0 | 0 | 4 (3) | 0
Bilateral | 0 | 0 | 0 | 3 (3) | 0
Unilateral or bilateral | 0 | 0 | 0 | 7 (6) | 0
Discolored, mottled
Unilateral | 0 | 0 | 0 | 0 | 0
Bilateral | 0 | 2 (2) | 0 | 0 | 0
Unilateral or bilateral | 0 | 2 (2) | 0 | 0 | 0

^a^ Incidence presented as number of animals with lesion (number of litters). No statistical analysis was performed.

The reproductive performance and prenatal cohorts exposed to 10,000 or 30,000 ppm 2H4MBP displayed terminal/adjusted body weights that were significantly decreased (5%−8% and 18%−19%, respectively) compared to the control females (Table 31). Females in all 2H4MBP-exposed groups from both cohorts displayed significantly increased relative liver weights (10%–14%, 17%–32%, and 28%–53% in the 3,000, 10,000, and 30,000 ppm groups, respectively) compared to the control females (Table 31). Rats in the reproductive performance cohort exposed to 3,000, 10,000, and 30,000 ppm 2H4MBP displayed higher (approximately 5%−7%, 11%, and 24%−30%, respectively) relative right and left kidney weights compared to the control group. Absolute kidney weights were significantly decreased (12%−14%) compared to the control group in females in the reproductive performance cohort exposed to 0.05 ppm EE. Relative liver weights were significantly increased in the 0.05 ppm EE groups in both cohorts compared to the control groups, likely because necropsy body weights were lower than those of the control group.

Table 31 Summary of Organ Weights of Adult F_1_ Female Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed^a,b,c^

| 0 ppm | | 3,000 ppm | | 10,000 ppm | | 30,000 ppm | | EE 0.05 ppm^d^
| RPC | PC | RPC | PC | RPC | PC | RPC | PC | RPC | PC
No. of Litters Examined | 22 | 19 | 20 | 17 | 20 | 19 | 20 | 18 | 15 | 15
Necropsy Body Wt. (g)^e^ | 316.7 ± 4.6** | 315.5 ± 5.2** | 315.1 ± 3.4 | 304.5 ± 5.7 | 302.1 ± 3.1* | 291.6 ± 2.9** | 262.1 ± 3.6** | 256.8 ± 4.6** | 255.7 ± 3.8** | 249.5 ± 3.4**
Liver
Absolute (g) | 14.02 ± 0.41** | 15.18 ± 0.46 | 15.82 ± 0.36** | 16.15 ± 0.44 | 17.53 ± 0.37** | 16.38 ± 0.23 | 17.60 ± 0.54** | 15.80 ± 0.44 | 13.93 ± 0.32 | 12.83 ± 0.30**
Relative (mg/g)^f^ | 44.12 ± 1.08** | 48.07 ± 1.08** | 50.19 ± 1.02** | 53.02 ± 1.01** | 58.14 ± 1.25** | 56.17 ± 0.58** | 67.40 ± 2.11** | 61.42 ± 0.99** | 54.57 ± 1.16** | 51.43 ± 0.96*
R. Kidney
Absolute (g) | 1.14 ± 0.02 | – | 1.19 ± 0.02 | – | 1.21 ± 0.01 | – | 1.22 ± 0.04 | – | 0.98 ± 0.02** | –
Relative (mg/g) | 3.61 ± 0.05** | – | 3.78 ± 0.05 | – | 4.01 ± 0.04* | – | 4.70 ± 0.19** | – | 3.85 ± 0.06** | –
L. Kidney
Absolute (g) | 1.12 ± 0.02 | – | 1.19 ± 0.01* | – | 1.18 ± 0.01* | – | 1.14 ± 0.02 | – | 0.98 ± 0.02** | –
Relative (mg/g) | 3.53 ± 0.05** | – | 3.79 ± 0.04** | – | 3.92 ± 0.04** | – | 4.37 ± 0.07** | – | 3.86 ± 0.07** | –
Adrenal Glands
Absolute (g) | 0.071 ± 0.001** | 0.073 ± 0.002 | 0.067 ± 0.001 | 0.066 ± 0.002 | 0.068 ± 0.001 | 0.066 ± 0.003 | 0.060 ± 0.002** | 0.070 ± 0.003 | 0.059 ± 0.001** | 0.056 ± 0.002**
Relative (mg/g) | 0.23 ± 0.01 | 0.23 ± 0.01** | 0.21 ± 0.00 | 0.22 ± 0.001 | 0.22 ± 0.001 | 0.23 ± 0.01 | 0.23 ± 0.01 | 0.27 ± 0.01** | 0.23 ± 0.01 | 0.22 ± 0.01
R. Ovary
Absolute (g) | 0.075 ± 0.003** | 0.106 ± 0.005** | 0.068 ± 0.002 | 0.092 ± 0.005* | 0.066 ± 0.003 | 0.093 ± 0.005* | 0.058 ± 0.003** | 0.084 ± 0.003** | 0.055 ± 0.003** | 0.075 ± 0.004**
L. Ovary^g^
Absolute (g) | 0.071 ± 0.002** | 0.096 ± 0.006* | 0.071 ± 0.002 | 0.101 ± 0.003 | 0.068 ± 0.003 | 0.085 ± 0.005 | 0.059 ± 0.003** | 0.085 ± 0.005 | 0.063 ± 0.004 | 0.069 ± 0.005**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol; RPC = reproductive performance cohort; PC = prenatal cohort.

^a^ Data for the RPC and PC are also presented separately by cohort in Appendix E.

^b^ Data displayed as mean [underlined: +] standard error of the litter means.

^c^ Statistical analysis for the RPC performed using the Jonckheere (trend) and Williams or Dunnett (pairwise) tests. Statistical analysis for the PC performed using mixed models with a random effect for litter and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^d^ The EE group was not included in any trend analysis; it was included in the pairwise analysis to the vehicle control group.

^e^ The terminal body weight for the prenatal females is the final body weight minus the gravid uterine weight.

^f^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

^g^ n = 19 for the 10,000 ppm group in the RPC. The decrease is due to one female's value being excluded because it was an outlier.

Females exposed to 10,000 or 30,000 ppm 2H4MBP in both cohorts displayed lower absolute right and left ovarian weights (Table 31). Females in the reproductive performance cohort exposed to 30,000 ppm 2H4MBP displayed significantly decreased absolute adrenal gland weight compared to the control group. Both cohorts of the EE groups had lower absolute ovarian and adrenal gland weights. These changes are likely the result of lower body weights of exposed animals relative to control animals.

#### F_2_ Necropsy

Pups were euthanized on PND 28; gross pathology findings are reported in Appendix E. One male each in the 3,000 and 30,000 ppm 2H4MBP groups exhibited bilateral undescended testes. Three males each in the 3,000 and 10,000 ppm 2H4MBP groups exhibited unilateral undescended testes. Several females in the 30,000 ppm 2H4MBP group displayed dilated, discolored, or enlarged kidneys consistent with what was observed in adults. Diaphragmatic hernias were observed in three males in the 30,000 ppm 2H4MBP group and in one male in the EE group (Appendix E). Diaphragmatic hernias were also observed in 2H4MBP- or EE-exposed F_1_ rats in the reproductive performance cohort (Appendix E). The collective EE group had two males with diaphragmatic hernias. No hernias were observed in control animals or in the F_0_ females (Appendix E). These hernias consist of a small protrusion of the liver through the diaphragm and are sometimes recorded grossly as diaphragmatic hernias and sometimes as hepatodiaphragmatic hernias.

### Pathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions. Summaries of the incidences of nonneoplastic lesions mentioned in this section are presented as supplemental data in Appendix E.

Kidney: The kidney was the primary target of 2H4MBP exposure (Table 32; Appendix E). In the F_1_ reproductive performance cohort, the incidences of renal tubule epithelial regeneration were significantly increased in the 30,000 ppm males and females relative to their respective control groups; a higher incidence of this lesion was also noted in the 10,000 ppm females. When compared to control animals, both male and female rats exposed to 30,000 ppm had significantly increased incidences of interstitial chronic active inflammation, renal tubule concretions, renal tubule dilation, urothelial hyperplasia, and urothelial ulcers. In the F_1_ reproductive performance cohort, pelvic concretion and papillary necrosis was significantly increased compared to control animals in the 30,000 ppm males, and there was a positive trend for pelvic concretion and papillary necrosis in the females. F_1_ females in the reproductive performance cohort also had significantly increased incidences of renal tubule epithelial degeneration (30,000 ppm), chronic progressive nephropathy (3,000 and 10,000 ppm), and mineralization (3,000 and 10,000 ppm) compared to control animals, and there was a positive trend for pelvic dilation. Renal lesions were also observed in the F_0_ and other cohorts (see below).

Table 32 Incidences of Nonneoplastic Lesions of the Kidney in Adult F_1_ Male and Female Rats in the Reproductive Performance Cohort Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed^a^

| 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.5 ppm
Male^b^ | 41 (22) | 40 (20) | 40 (21) | 40 (20) | 0 (15)
Renal tubule, epithelium, regeneration^c^ | 0** | 0 | 0 | 33 (17)** [1.2]^d^ | –^e^
Interstitium, inflammation, chronic active | 0** | 0 | 0 | 22 (14)** [1.7] | –
Renal tubule, concretion | 0** | 0 | 0 | 35 (19)** [1.4] | –
Pelvis, concretion | 0** | 0 | 0 | 17 (13)** [1.5] | –
Renal tubule, dilation | 0** | 0 | 0 | 37 (20)** [1.5] | –
Urothelium, hyperplasia, total | 0** | 1 (1) [1.0] | 0 | 18 (15)** [1.3] | –
Urothelium, ulcer | 0** | 0 | 0 | 12 (9)** [1.0] | –
Papilla, necrosis | 0** | 0 | 0 | 10 (10)** [1.3] | –
Female | 35 (22) | 37 (20) | 33 (20) | 32 (20) | 0 (15)
Renal tubule, epithelium, regeneration | 0** | 0 | 3 (3) [1.0] | 13 (12)** [1.5] | –
Interstitium, inflammation, chronic active | 0** | 0 | 0 | 8 (8)* [1.4] | –
Renal tubule, concretion | 0** | 0 | 0 | 13 (12)** [1.4] | –
Pelvis, concretion | 0** | 0 | 0 | 9 (5) [1.0] | –
Renal tubule, dilation | 0** | 0 | 0 | 28 (19)** [1.4] | –
Urothelium, hyperplasia, diffuse | 0** | 0 | 0 | 15 (12)** [1.3] | –
Urothelium, ulcer | 0** | 0 | 0 | 6 (6)* [1.0] | –
Papilla, necrosis | 0* | 0 | 0 | 4 (3) [1.0] | –
Renal tubule, epithelium, degeneration | 0** | 0 | 0 | 21 (14)** [1.1] | –
Pelvis, dilation, total | 0* | 1 (1) [3.0] | 0 | 5 (5) [2.0] | –
Chronic progressive nephropathy | 18 (14) [1.1] | 35 (19)** [1.1] | 29 (19)** [1.0] | 22 (17) [1.0] | –
Mineralization | 9 (8) [1.0] | 28 (17)** [1.0] | 24 (18)** [1.0] | 10 (8) [1.2] | –

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EE = ethinyl estradiol.

^a^ Statistical analysis performed using the Cochran-Armitage test with a Poly-3 adjustment for age and a Rao-Scott modification for the random effect due to litter.

^b^ Number of animals (number of litters) with tissue examined microscopically.

^c^ Number of animals (number of litters) with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ Nonneoplastic lesions were not evaluated in the EE group.

Interstitial chronic active inflammation was characterized by a mixture of inflammatory cell types, including neutrophils, lymphocytes, and macrophages, with some fibrosis. This lesion was distinct from the interstitial infiltrates of mononuclear cells that accompanies chronic progressive nephropathy. When the renal papilla was necrotic, it was frequently no longer visible in the section of tissue, with just eosinophilic amorphous material present where the tip of the papilla should be. When the necrotic papilla was still present in the section, it was characterized by a pale, washed out, eosinophilic color and lack of cellular detail. Renal tubule dilation was the most frequently observed change in the kidneys of male and female rats and was frequently accompanied by intratubular accumulations of round or angular pale-brown to red-brown material, often with a laminated appearance. These renal tubular concretions were similar to the pelvic concretions. Other dilated renal tubules contained proteinaceous casts, characterized by homogenous, bright eosinophilic material, or cell debris. Renal tubule dilation was generally a focal change, most often involving the poles of the kidney, which affected the entire length of the nephron. The epithelium lining the dilated tubules was flattened and frequently showed evidence of degeneration (females) or regeneration (males and females).

Renal tubule epithelial degeneration was characterized by the absence of epithelial cells or the presence of individual necrotic epithelial cells, whereas renal tubule epithelial regeneration was characterized by plump epithelial cells with basophilic cytoplasm that projected into the tubular lumen. Regeneration most likely occurred after degeneration, and the lack of observed degeneration in the males might imply a quicker onset or a more severe course of renal tubular epithelial degeneration in male rats relative to female rats. Urothelial hyperplasia consisted of an increased number of cell layers of the epithelium lining the renal pelvis and occurred as either a focal (males) or diffuse (males and females) change. The severity of the lesion was based on the thickness of the hyperplasia as well as on the amount of pelvis involved, with focal lesions being less severe than those involving the entire renal pelvis (diffuse). Urothelial hyperplasia was usually of minimal to mild severity, but in one female rat, moderate urothelial hyperplasia was accompanied by squamous metaplasia of the urothelium. Ulceration of the urothelium was characterized by a focal area devoid of epithelium. Roughly half of the animals with ulcers of the urothelium also had urothelial hyperplasia. One male rat had necrosis of the urothelium; focal necrosis typically develops into an ulcer as the necrotic epithelium is sloughed off. Pelvic dilation was characterized by an increased space between the renal papilla and the renal pelvis. In most cases, papillary necrosis was evidenced by the absence of the tip of the papilla and accumulations of pale, eosinophilic material where the tip of the papilla should be. Occasionally, the tip of the papilla was still in place but was pale and lacked nuclear detail. Most occurrences of chronic progressive nephropathy were of minimal or mild severity; minimal nephropathy consisted of basophilic tubules with a thickened basement membrane, whereas mild cases of nephropathy typically also had tubular proteinaceous casts and mixed mononuclear cell inflammation within the interstitium. Mineralization was characterized by small focal deposits of deeply basophilic granular material, typically along the corticomedullary junction; evidence of minimal secondary renal tubule necrosis was occasionally associated with mineral deposition but not recorded separately.

The various renal lesions associated with exposure to 30,000 ppm 2H4MBP were consistent with an obstructive nephropathy. Obstructive nephropathy occurs when something restricts the outflow of urine, such as crystals, with subsequent inflammation or a lower urinary tract blockage. Retrograde nephropathy, which is a form of obstructive nephropathy, is due to urine backflow into the kidney, causing tubule dilation that ascends from the papilla to the cortex.^100,101^

F_0_ females, F_1_ males in the prenatal cohort, and F_2_ males and females were also necropsied; however, only lesions that were grossly visible at the time of necropsy were examined histologically. Only one F_1_ female from the prenatal cohort, a 3,000 ppm 2H4MBP group animal, was examined histologically, and there were no gross or histological lesions of the kidney. In the F_0_ females, 0, 0, 1, and 7 animals from the 0, 3,000, 10,000, and 30,000 ppm 2H4MBP groups had gross lesions, and 0, 0, 0, and 3 had gross lesions of the kidneys, respectively. The three F_0_ females in the 30,000 ppm group had pale kidneys observed at necropsy; this observation was associated histologically with various kidney lesions, including renal tubule dilation, renal tubule epithelial regeneration, interstitial chronic active inflammation, papillary necrosis, and urothelial hyperplasia. In F_1_ males from the prenatal cohort, 2, 1, 2, and 15 animals from the 0, 3,000, 10,000, and 30,000 ppm 2H4MBP groups had gross lesions, of which 0, 0, 2, and 13 animals had gross lesions of the kidneys, respectively. Gross lesions included enlarged and discolored kidneys in the 30,000 ppm group and dilated pelvis in the 10,000 ppm group. Histologically, the kidneys from the 30,000 ppm group had papillary necrosis and pelvic concretions, renal tubule dilation and concretions, renal tubule epithelial regeneration, and hyperplasia and ulceration of the urothelium; the kidneys from females in the 10,000 ppm group had pelvic dilation.

In the F_2_ males, 2, 5, 6, and 6 animals from the respective 0, 3,000, 10,000, and 30,000 ppm 2H4MBP groups had gross lesions, of which 1, 0, 3, and 0 had gross lesions of the kidneys. Gross lesions included discoloration and pelvic dilation, which were seen histologically as congestion and pelvic dilation. In the F_2_ females, 2, 1, 0, and 8 animals had gross lesions from the respective 0, 3,000, 10,000, and 30,000 ppm 2H4MBP groups, of which 1, 0, 0, and 7 had gross lesions of the kidneys. Histological findings associated with these gross findings included renal tubule and pelvic dilation (Appendix E).

Urinary Bladder: In F_1_ males from the reproductive performance cohort exposed to 30,000 ppm 2H4MBP, there was an increase, although not significant, in the incidences of urinary bladder concretions (Appendix E). Most of these animals had gross observations of brown discoloration in the urinary bladder.

Liver: Hepatodiaphragmatic hernias (HDN) occurred at a low incidence in the 10,000 and 30,000 ppm males and females and in the 3,000 ppm females in the F_1_ reproductive performance cohort (0, 0, 1, 1 for the 0, 3,000, 10,000, and 30,000 ppm males, respectively; 0, 2, 1, 4 for the 0, 3,000, 10,000, and 30,000 ppm females, respectively). Although none of the incidences was statistically different from control animals, no occurrences of HDN were observed in either the male or female control groups (Table 33). All but two of the HDNs (one in the 10,000 ppm males and one in the 30,000 ppm females) correlated with gross observations of diaphragmatic hernias at necropsy. HDNs were rounded protrusions of the liver that were histologically similar to normal liver.

Table 33 Incidences of Diaphragmatic Hernias and Hepatodiaphragmatic Hernias in Adult F_1_ Male and Female Rats in the Reproductive Performance Cohort and F_2_ Male Rats Exposed to 2-Hydroxy-4-methoxybenzophenone in Feed

| 0 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm | EE 0.5 ppm
F_1_ Male
Diaphragm, hernia^a^ | 0 41 [22]^c^ | 0 40 [20] | 0 40 [21] | 1 (1)^b^ 40 [20] | 1 (1) 30 [15]
Hepatodiaphragmatic hernia^d^ | 0 41 [22]^e^ | 0 40 [20] | 1 (1) 40 [21] | 1 (1) 40 [20] | 1 (1) 2 [15]
F_1_ Female
Diaphragm, hernia | 0 41 [22] | 2 (2) 40 [20] | 1 (1) 40 [21] | 3 (2) 40 [20] | 0 30 [15]
Hepatodiaphragmatic hernia | 0 35 [22] | 2 (2) 2 [20] | 1 (1) 1 [20] | 4 (3) 32 [20] | 0 0 [15]
F_2_ Male
Diaphragm, hernia | 0 91 [30] | 0 110 [34] | 0 101 [32] | 3 (3) 88 [30] | 1 (1) 87 [27]

EE = ethinyl estradiol.

^a^ No statistical analysis was performed.

^b^ Number of animals with lesion (number of litters).

^c^ Number of animals examined for gross lesions [number of litters].

^d^ Statistical analysis performed using the Cochran-Armitage test with a Poly-3 adjustment for age and a Rao-Scott modification for the random effect due to litter.

^e^ Number of animals with tissue examined microscopically [number of litters].

Preputial Gland: There was a significant increase in the incidence of preputial gland, duct ectasia in F_1_ males in the reproductive performance cohort exposed to 30,000 ppm 2H4MBP (Appendix E). This lesion consists of a dilation of the ducts of the preputial gland and is a common background change seen in rats, especially as they age. In its most severe form, ectatic ducts become cystic or even rupture, inciting a marked inflammatory reaction. The average severities of these lesions were between minimal and mild in the control group and exposed groups. The biological importance of this lesion is unknown.