# Materials and Methods

## Overview of Pre- and Postnatal Dose Range-finding and Modified One-Generation Study Designs

Modified one-generation (MOG) studies are composed of two interrelated parts: (1) a dose range-finding study (Figure 3) and (2) a MOG study (Figure 4, Table 1). If the acceptable range of exposure concentrations required to avoid excessive general and perinatal toxicity is unknown, a pre- and postnatal dose range-finding study is conducted. Nulliparous females are mated at the animal vendor and sent to the testing laboratory. Dosing typically begins at implantation (gestation day [GD] 6) through weaning on lactation day (LD) 28. Offspring are exposed in utero, during lactation, and through consumption of dosed feed.

Figure 3

Design of a Dose Range-finding Study

F_0_ dams are exposed to the test article from gestation day (GD) 6 through weaning on lactation day (LD) 28 and evaluated for maternal toxicity. F_1_ offspring are exposed in utero through postnatal day (PND) 28 and evaluated for signs of in utero and postnatal toxicity.

Figure 4

Design of a Modified One-Generation Rat Study

F_0_ dams are exposed to the test article from gestation day (GD) 6 through weaning on lactation day (LD) 28 and evaluated for maternal toxicity. F_1_ offspring are exposed in utero and during lactation through postnatal (PND) 28 and evaluated for signs of toxicity. After weaning, F_1_ offspring are allocated into cohorts for prenatal, reproductive performance, or additional assessments (e.g., subchronic or biological sampling cohorts) and exposure to test article continues until necropsy. F_2_ offspring are exposed in utero and during lactation and postweaning until necropsy (reproductive performance cohort).

Table 1 Key Modified One-Generation Study Design Endpoints

Cohort | Key Endpoints
F_0_ Dams | Maternal toxicity endpoints (body weight, feed consumption, clinical observations)
F_1_ Generation^a^ | Clinical observations
| Body weights
| Feed consumption
| Necropsy
| Pup survival
| Anogenital distance, nipple/areola retention, testis descent, vaginal cytology
Reproductive Performance Cohort | F_1_ reproductive performance
| F_1_ andrology and sperm parameters
| F_1_ histopathology
| F_2_ litter size, viability, and growth
| F_2_ necropsy
Prenatal Cohort | F_1_ reproductive performance
| F_2_ fetal external, visceral, skeletal, and head soft tissue examinations
| F_2_ necropsy
Subchronic Cohort | F_1_ hematology
| F_1_ clinical chemistry
| F_1_ histopathology

^a^ Additional cohorts (e.g., biological sampling cohort) and associated endpoints may be included in the study design.

In MOG studies, time-mated females are administered the test article from GD 6 through weaning (evidence of mating = GD 0). The subsequent F_1_ litters are standardized to a specified litter size (n = 8 or 10), with equal representation of both sexes. These offspring are continuously exposed to the test article via the same route of exposure and dose concentration as their dams. Multiple endpoints indicative of potential endocrine alteration (e.g., anogenital distance [AGD], nipple retention in males, pubertal markers) are measured (Table 1). Randomly selected F_1_ animals are taken to adulthood for gross and histopathological examinations and can be allocated at weaning (postnatal day [PND] 28) to various cohorts. Histopathological examination of multiple animals per litter increases the power of statistical tests to detect adverse effects.^58^

The ability of F_1_ animals to mate and produce viable offspring is evaluated in the reproductive performance cohort. The potential for the test article to induce fetal defects is assessed in the prenatal cohort: F_2_ fetuses are examined on GD 21, which includes examination of external morphology, fetal viscera, head (soft tissue and skeletal components), and skeleton (osseous and cartilaginous defects). Abnormalities are categorized as either malformations, which are permanent structural changes that could adversely affect survival, development, or function; or variations, which are a divergence beyond the usual range of structural constitution that might not adversely affect survival or health,^59^ consistent with descriptions by Makris et al.^60^ Endpoints common to most cohorts are described in Table 1.

Subchronic toxicity, including effects on clinical chemistry and hematology, are assessed in a 3-month cohort. Other cohorts can also be added (e.g., for internal dose estimation, neurobehavioral, toxicokinetic, and/or immunotoxicity assessments) to identify potential hazards across multiple functional outcomes. If necessary, more than one animal per sex can be selected from each litter and assigned to a cohort (e.g., reproductive performance). The F_1_ litter remains the statistical unit but examining multiple animals per litter increases the likelihood of detecting adverse responses and collectively makes the most use of the animals produced.

In the studies reported here, F_0_ females were administered the test article in feed beginning on GD 6. F_1_ and F_2_ offspring were exposed in utero, during lactation, and through consumption of dosed feed.

## Procurement and Characterization

### 2-Hydroxy-4-methoxybenzophenone

2-Hydroxy-4-methoxybenzophenone (2H4MBP) was obtained from Ivy Fine Chemicals (Cherry Hill, NJ) in a single lot (20100801), which was used in the dose range-finding and MOG studies. Identity and purity analyses were conducted under the analytical chemistry laboratory and study laboratory at Battelle (Columbus, OH) (Appendix A). Reports on analyses performed in support of the 2H4MBP studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot 20100801 of the chemical, a light-yellow powder, was identified as 2H4MBP by infrared (IR) and ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopy. The IR spectrum was in good agreement with a reference spectrum (BP #824 from the Sadtler Basic Monomers and Polymers Library [Bio-Rad Laboratories, Hercules, CA]) and the structure of 2H4MBP. ^1^H and ^13^C NMR spectra were consistent with computer-predicted spectra and the structure of the test article.

The purity of 2H4MBP lot 20100801 was determined using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection, as well as gas chromatography (GC) with flame ionization detection (FID). Lot 20100801 was screened for common residual volatile solvents using GC with electron capture detection (ECD) and FID. Differential scanning calorimetry (DSC) was also used to determine the purity of 2H4MBP. Karl Fisher titration of 2H4MBP lot 20100801 was conducted to estimate moisture content.

Purity assessment by HPLC/UV and GC/FID found one major peak with no reportable impurities ≥0.1%. Purity by DSC was 99.9%. Karl Fischer analysis indicated that no quantifiable water was present in 2H4MBP lot 20100801. No significant halogenated or nonhalogenated volatile impurities were found in the lot. The overall purity of 2H4MBP lot 20100801 was determined to be >99%.

To ensure stability, the bulk 2H4MBP was stored at room temperature (approximately 25°C) in sealed amber glass containers. Periodic analysis of the lot by the study laboratory using HPLC/UV showed no degradation of the bulk 2H4MBP chemical.

### Ethinyl Estradiol

Ethinyl estradiol (EE) was obtained in a single lot (090M1241V) from Sigma-Aldrich (St. Louis, MO) via Government Scientific Source, Inc. (Reston, VA). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH) (Appendix A).

EE lot 090M1241V was a white powder. The lot identity was confirmed using IR spectroscopy and ^1^H and ^13^C NMR spectroscopy; all spectra were consistent with the structure of EE and matched available reference and predicted spectra. Elemental analysis indicated that the sample was approximately 80.4% carbon, 11.5% oxygen, 7.9% hydrogen, and >0.5% nitrogen, which is consistent with theoretical values.

HPLC/UV showed a major peak with 99.8% and one minor peak with 0.23% of the total peak area, and analysis for volatiles using headspace GC/FID found the sample contained approximately 0.023% acetone. DSC yielded a purity of 99.7% and a melting point of 184°C. Karl Fischer analysis indicated that the water content of lot 090M1241V was approximately 0.4%. These data indicated the EE purity of lot 090M1241V to be ≥99.7%, consistent with the manufacturer-reported purity of 99%.

To ensure stability, the EE positive control was stored in sealed glass containers at room temperature. Prior to the study and at study termination, lot 090M1241V was analyzed using HPLC/UV to ensure chemical stability.

## Preparation and Analysis of Dose Formulations

### 2-Hydroxy-4-methoxybenzophenone

Dosed feed formulations were prepared monthly (dose range-finding study) or eight times (MOG study) (Table A-2) using irradiated low-phytoestrogen feed (5K96 Casein diet). Formulations were stored at approximately 5°C for up to 42 days in amber glass bottles. The homogeneity of 2H4MBP formulations in 5K96 feed was confirmed before conducting the studies. The analytical chemistry laboratory at Battelle (Columbus, OH) conducted all dose formulation analyses throughout the study.

Stability studies conducted on a 1,000 ppm formulation when sealed and stored in amber plastic bags for 42 days at 5°C or −20°C showed that the formulation was within 10% of the day 0 value. An animal room simulation of a 1,000 ppm formulation stored in open glass containers at room temperature, with and without rodent urine and feces, showed that 2H4MBP over 7 days was within 10% of the day 0 concentration. The preadministration dosed feed formulations were analyzed three times over the course of the study (Table A-3, Table A-4) using HPLC/UV. All preadministration samples were within 10% of the target concentration except one 25,000 ppm formulation, which was 15.2% above the target concentration. For one set of dosed feed formulations, postadministration samples were collected from the animal room approximately 1 month after preparation. These formulations were also within 10% of the target concentrations.

### Ethinyl Estradiol

Dosed feed formulations were prepared eight times (Table A-2) using 5K96 feed. Formulations were stored at −20°C for ≤57 days in sealed amber plastic bags. The homogeneity of 0.05 ppm EE formulations in 5K96 feed was confirmed before conducting the studies.

Stability studies conducted on the 0.05 ppm formulation, when stored in sealed amber plastic bags at −20°C, approximately 5°C, or room temperature for 57 days, showed that the formulation was within 10% of the day 0 value. An animal room simulation of the 0.05 ppm formulation in open glass containers, with and without rodent urine and feces, showed that EE over 8 days was within 10% of the day 0 value.

The preadministration dosed feed formulations were analyzed four times over the course of the study (Table A-4) using HPLC/UV. All preadministration samples were within 10% of the target concentration with the exception of two formulations, one of which was 11% below and the other 12% above. Postadministration samples were collected from the animal room at the end of the exposure period and sent to Battelle (Columbus, OH) for analysis. The concentrations of the animal room samples were within 10% of the preadministration analyses and, therefore, demonstrated acceptable stability during the study.

## Animal Source

Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Dublin, VA) for use in the dose range-finding and MOG studies. Sexually mature (12 to 13 weeks old) females were time-mated overnight at the vendor and were received on GD 1 or GD 2 (13 to 15 weeks old) for both the dose range-finding and MOG studies. GD 0 was defined as the day positive evidence of mating was observed.

## Animal Health Surveillance

In accordance with the National Toxicology Program (NTP) Sentinel Animal Program (Appendix C), 20 nonmated female rats were designated for disease monitoring after arrival; samples were collected for serological analyses, and the rats were euthanized, necropsied, and examined for the presence of disease or parasites. All test results were negative.

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Laboratory Animals. All animal studies were conducted in a facility accredited by AAALAC International. Studies were approved by the RTI International Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Experimental Design

### Dose Range-finding Study

Time-mated female rats were received on GD 1 or GD 2, randomized based on GD 3 body weight, and placed on a 5K96 Casein diet containing 0, 3,000, 10,000, 25,000, or 50,000 ppm 2H4MBP from GD 6 through LD 28. Feed and water were available ad libitum; information on feed composition and contaminants is provided in Appendix B. Dose selection was based in part on Fischer 344/N rat studies reported in NTP Toxicity Report 21.^40^ Altering the concentration of 2H4MBP in the diet, reflecting changes in feed consumption as a function of time and life stage, was considered. However, given the challenges of having multiple feed concentrations at an anticipated projected daily dose level and different life stages, overrode the possibility.

Eight time-mated rats were allocated to each exposure group. Six additional time-mated female rats were allocated to the control, 3,000, and 50,000 ppm groups for collection of tissues for bioanalytical method development. Viability, clinical observations, body weights, pup counts (litters were not standardized), and feed consumption were recorded to help determine the maximum exposure concentration that could be tolerated by the dams while not affecting the number of pups, so the MOG study could be populated with a sufficient number of offspring. Maternal plasma, amniotic fluid, and fetuses were collected from three separately allocated dams on GD 18. On LD 4 and PND 4, maternal plasma and pups (three per sex), respectively, were collected from two to three dams per group. On LD 28, a piece of the left lateral lobe of the liver, left and right kidneys, left and right ovaries, and uterus were collected from five dams per group. In addition, left and right testes, left and right epididymides, and the brain were collected from 10 male pups per group on PND 28. All other dams and pups were euthanized without further examination on LD 28 and PND 28, respectively. Females that did not litter were euthanized approximately 5 days after expected littering, received a gross necropsy, and had their pregnancy status determined. If present, the numbers of implantation sites were recorded. F_1_ pups that were removed for health reasons or morbidity received a gross necropsy. Further details of animal maintenance and study design are given in Table 2.

Table 2 Experimental Design and Materials and Methods in the Dose Range-finding and Modified One-Generation Studies of 2-Hydroxy-4-methoxybenzophenone (Preweaning)

Dose Range-finding Study | Modified One-Generation Study
Study Laboratory
RTI International (Research Triangle Park, NC) | Same as dose range-finding study
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Same as dose range-finding study
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Dublin, VA) | Same as dose range-finding study
Day of Arrival
July 19, 2011 (GD 1 or GD 2) | February 14 or 16, 2012 (GD 1 or GD 2)
Average Age on Arrival
13–15 weeks | 13–15 weeks
Weight Range at Randomization
179.1–236.1 g on GD 3 | 186.4–258.8 g on GD 3
Date of First Exposure
GD 6 (July 23, 2011) | F_0_ females: GD 6 (February 18–21, 2012)
| F_1_ rats (all cohorts): lifetime exposure
| F_2_ rats: lifetime exposure
Duration of Exposure
GD 6 through LD 28 | F_0_ females: GD 6 through LD 28
| F_1_ rats (biosampling cohort): lifetime exposure through PND 56
| F_1_ rats (prenatal cohort): lifetime exposure through PND 111–113 (males) or through PND 109–132 (females)
| F_1_ rats (reproductive performance cohort): lifetime exposure through PND 153–155 (males) or through PND 127–168 (females)
| F_2_ rats (reproductive performance cohort): in utero through PND 28
Date of Last Exposure
LD 28 (September 7, 2011) | F_0_ females: LD 28 (April 2–6, 2012)
| F_1_ rats (biosampling cohort): PND 56 (May 2, 2012)
| F_1_ rats (prenatal cohort): PND 111–113 (through June 28, 2012) (males) or PND 116–132 (through July 15, 2012) (females)
| F_1_ rats (reproductive performance cohort): PND 153–155 (through August 10, 2012) (males) or PND 127–168 (through August 21, 2012) (females)
| F_2_ rats (reproductive performance cohort): PND 28 (through August 21, 2012)
Necropsy Dates
Gross necropsies were conducted on F_0_ females that did not deliver a litter or were euthanized early and F_1_ offspring that were euthanized moribund or found dead. | F_0_ females: LD 28 (April 2–6, 2012)
| F_1_ rats (biosampling cohort): not performed
| F_1_ rats (prenatal cohort): June 26–28, 2012 (males) or July 2–15, 2012 (females)
| F_1_ rats (reproductive performance cohort): August 6–10, 2012 (males) or August 7–21, 2012 (females)
| F_2_ rats (reproductive performance cohort): August 7–21, 2012
Average Age at Necropsy
Not performed | F_0_ females: ~21 weeks
| F_1_ rats (biosampling cohort): not performed
| F_1_ rats (prenatal cohort): 111–113 days (males) or 109–132 days (females)
| F_1_ rats (reproductive performance cohort): 153–155 days (males) or 127–168 days (females)
| F_2_ rats: 28 days
Size of F_0_ Study Groups
8–14 time-mated females | 25 time-mated females
Method of Randomization and Identification
Time-mated animals were individually identified by ink tail marking and assigned to exposure group by stratified randomization of GD 3 body weights using Provantis^®^ (Instem, Stone, United Kingdom) electronic data collection system. | Same as dose range-finding study, except F_1_ and F_2_ pups were identified by ink paw marking, and postweaning F_1_ males and F_1_ females were identified by ink tail marking.
Animals per Cage
1 (with litter) | F_0_ females: 1 (with litter)
| F_1_ rats (biosampling cohort): ≤2 (males or females) until approximate termination
| F_1_ rats (prenatal cohort): ≤2 (males or females) until approximate PND 91
| F_1_ rats (reproductive performance cohort): ≤2 (males or females) until PND 91, then housed individually except during cohabitation or when housed with their litters
Diet
Irradiated certified Advanced Protocol Verified Casein Diet 1 IF 5K96 (PMI Nutrition International, Richmond, IN), available ad libitum | Irradiated certified Advanced Protocol Verified Casein Diet 1 IF 5K96 (PMI Nutrition International, St. Louis, MO), available ad libitum
Water
Tap water (Durham, NC) via automatic watering system (Avidity Science, formerly Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as dose range-finding study
Cages
Solid-bottom polycarbonate cages (Lab Products, Inc., Seaford, DE), rotated once weekly and changed at least once/week | Same as dose range-finding study
Bedding
Certified irradiated Sani-Chips^®^ hardwood cage bedding (P.J. Murphy Forest Products Corp., Montville, NJ) | Same as dose range-finding study
Cage Filters
Filter paper (Granville Milling Co., Creedmoor, NC), changed weekly | Same as dose range-finding study
Racks
Stainless steel (Ancare, Bellmore, NY), changed and rotated every 2 weeks during the study | Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks during the study
Animal Room Environment
Temperature: 71.05°F to 72.8°F Relative humidity: 39.98% to 55.91% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Exposure Concentrations
0, 3,000, 10,000, 25,000, or 50,000 ppm 2H4MBP in feed, available ad libitum | 0, 3,000, 10,000, or 30,000 ppm 2H4MBP in feed, available ad libitum; 0.05 ppm EE in feed, available ad libitum
Type and Frequency of Observation of F_0_ and F_1_ Dams
Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. Female body weights were recorded daily during gestation (GD 3–21) and during lactation on LDs 1, 4, 7, 14, 21, 25, and 28. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21 and for LDs 1–4, 4–7, 7–14, 14–21, 21–25, and 25–28. | Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. Female body weights were recorded daily during gestation (GD 3–21) and during lactation on LDs 1, 4, 7, 10, 13, 16, 19, 21, 25, and 28. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21 and LD 1 through LD 28.
Type and Frequency of Observation of F_1_ and F_2_ Pups
Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. The number of live and dead pups in each litter was counted daily. Individual pups were sexed and weighed on PNDs 1, 4, 7, 14, 21, 25, and 28. Litters were not standardized on PND 4, and all offspring (unless euthanized and biological samples collected for subsequent analytical method development) were retained until PND 28 to assess litter size, sex distribution, pup body weights, and survival during lactation. | Viability was assessed at least twice daily, and clinical observations were recorded at least once daily. The number of live and dead pups in each litter was counted daily. Individual pups were sexed and weighed on PNDs 1, 4, 7, 10, 13, 16, 19, 21, 25, and 28. Litters were standardized to a litter size of 8 pups (4/sex/litter, when possible) on PND 4. Endocrine F_1_/F_2_ endpoints: AGD and corresponding pup weight on PND 1; areolae/nipple retention on PND 13; testicular descent beginning on PND 14
Primary Method of Euthanasia
100% carbon dioxide (F_0_ females and PND 28 pups); intraperitoneal injection of a solution containing sodium pentobarbital or decapitation (GD 21 fetuses; PND 4 pups) | 100% carbon dioxide (adults and PND 28 pups) or administration of a solution containing sodium pentobarbital (PND 4 pups [intraperitoneal injection]; GD 21 fetuses [oral])
Necropsy and Postmortem Evaluation
F_0_ dams were euthanized on LD 28 without necropsy. Females that did not litter were euthanized ~5 days after expected littering, received a gross necropsy, and had their pregnancy status determined. If present, the numbers of implantation sites and corpora lutea were recorded. F_1_ pups that were removed for health reasons or died received a gross necropsy. | F_0_ dams were euthanized on LD 28, received a gross necropsy, and had their number of implantation sites recorded. Females that did not litter were euthanized 3 days after expected littering, received a gross necropsy, and had their pregnancy status determined. If present, the number of implantation sites and corpora lutea were recorded. Histopathological analysis of gross lesions was performed if collected.
Internal Dose Assessment/Additional Tissue Collection
On GD 18, maternal plasma, amniotic fluid, and fetuses were collected from 3 pregnant dams/exposure group from the 0, 3,000, and 50,000 ppm groups. On LD 4, maternal plasma was collected from 2 or 3 dams/exposure group from the 0, 3,000, and 50,000 ppm groups. On PND 4, pups (3/sex) were collected from 2 or 3 dams/exposure group from the 0, 3,000, and 50,000 ppm groups. On LD 28, a piece of the left lateral lobe of the liver, left and right kidneys, left and right ovaries, and uterus were collected from 5 dams/exposure group. In addition, left and right testes, left and right epididymides, and the brain were collected from 10 male pups/exposure group on PND 28. Sample collection preceded the analytical method protocol development and method validation. Following the analysis and evaluation of a sample subset, the analysis of the full sample set was not pursued due to potential instability of analytes during long-term storage. | On PNDs 28 and 56 (5/sex/time point/exposure group), kidneys, epididymides, testes, ovaries, and liver were collected from rats in the biological sampling cohort and frozen for potential future analyses. Plasma samples were also collected from these rats on PNDs 28 and 56 (5/sex/time point/exposure group) and analyzed for 2H4MBP and metabolites.^68^

GD = gestation day; LD = lactation day; PND = postnatal day; 2H4MBP = 2-hydroxy-4-methoxybenzophenone; EE = ethinyl estradiol; AGD = anogenital distance.

### Modified One-Generation Study with Prenatal and Reproductive Performance Cohorts

Time-mated F_0_ female rats, 25 per group, were received on GDs 1 or 2, randomized based on GD 3 body weight, and placed on a 5K96 Casein diet containing 0, 3,000, 10,000, or 30,000 ppm 2H4MBP or 0.05 ppm EE ad libitum on GD 6. The exposure concentration of 30,000 ppm was expected to result in minimal maternal toxicity and to ensure that the model system was appropriately challenged, increasing the likelihood of identifying any toxicological signal in the offspring. The F_1_ and F_2_ generations were exposed to 2H4MBP or EE via the mother during gestation and lactation, and directly via 5K96 feed at the same exposure concentration as their respective dams. Viability, clinical observations, body weights, pup counts, and feed consumption were recorded. F_1_ and F_2_ litters were standardized to 8 pups (4/sex/litter, when possible) on PND 4. At weaning on PND 28, offspring were randomly assigned to reproductive performance (2/sex/litter), prenatal development (1/sex/litter), or biological sample collection (1/sex/litter) cohorts. Information on feed composition and contaminants is provided in Appendix B. Additional details of animal maintenance and study design are given in Table 2 and Table 3.

Table 3 Experimental Design and Materials and Methods in the Modified One-Generation Study of 2-Hydroxy-4-methoxybenzophenone (Postweaning)

Modified One-Generation Study
F_1_ Postweaning Assessments
All Cohorts: Viability was assessed at least twice daily, and clinical observations recorded at least once daily. F_1_ male body weights and feed consumption were recorded once weekly. F_1_ female body weights and feed consumption were recorded at least once weekly during the premating interval. Vaginal opening (and concomitant body weight) was evaluated beginning on PND 23, balanopreputial separation (and concomitant body weight) was evaluated beginning on PND 35.
Prenatal and Reproductive Performance Cohorts: After collection of vaginal lavage samples for 16 days, F_1_ nonsibling mating pairs (1 male and 1 female/litter or 2 males and 2 females/litter) from the same exposure group were cohabitated until evidence of mating or for ≤15 days. F_1_ dams were observed for the same gestational endpoints as the F_0_ dams.
Reproductive Performance Cohort: F_1_ dams and F_2_ pups were evaluated for the same lactational endpoints as the F_0_ dams and F_1_ pups. A crossover mating would have been considered if an effect on fertility was observed.
F_1_ Necropsy and Postmortem Evaluation
Prenatal Cohort: F_1_ dams were euthanized on GD 21. Necropsies were performed on all females. Terminal body weights and adrenal glands (paired), liver, ovaries (left and right), and gravid uterus weights were recorded. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses and resorptions (early or late) and the total number of implantation sites were recorded. If there were no macroscopic evidence of pregnancy, the uterus was stained to visualize potential evidence of implantation sites. Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities, including examination of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were euthanized and then examined for visceral morphological abnormalities by fresh dissection. The sex of each fetus was confirmed by internal examination. The heads from approximately one-half of the fetuses in each litter were fixed, sectioned, and examined. All fetuses were eviscerated, fixed, stained, and examined for skeletal developmental variations, malformations, or other morphological findings. After positive evidence of mating, male sires were weighed, euthanized, and necropsied, and the following organ weights recorded: adrenal glands (paired), testes (left and right), epididymides (left and right), kidneys, liver, dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, thyroid gland (fixed), LABC muscle, Cowper’s glands (paired), and preputial glands. Histopathology of gross lesions was assessed.
Reproductive Performance Cohort: F_1_ dams were euthanized on LD 28, and sires were euthanized within approximately 1 week of their mating partner. Terminal body weights and the following organ weights were recorded: adrenal glands (paired), liver, kidneys (left and right), ovaries (left and right), testes (left and right), epididymides (left and right), cauda epididymis, dorsolateral and ventral prostate gland, seminal vesicles with coagulating glands, thyroid gland (fixed), LABC muscle, Cowper’s glands (paired), and preputial glands. Histopathology was performed on the following organs (predominantly reproductive tissues): adrenal glands, liver, kidneys, pituitary gland, thyroid gland, ovaries, testes, epididymides, dorsolateral and ventral prostate gland, seminal vesicles, coagulating glands, LABC muscle, Cowper’s glands, preputial glands, and gross lesions. Cauda epididymal sperm motility, cauda epididymal sperm concentration, and testicular sperm head counts were also assessed.
Biological Sampling Cohort: At weaning, F_1_ rats were randomly allocated for collection of biological samples. Rats were subjected to a gross necropsy, and the following tissues were collected on PNDs 28 and 56 (5/sex/time point/exposure group): plasma, kidneys, epididymides, testes, ovaries, and liver. Tissues were frozen at −70°C until analysis. Results of the plasma analyses had been reported previously.^68^

PND = postnatal day; GD = gestation day; LABC = levator ani/bulbocavernosus; LD = lactation day.

#### Endocrine-sensitive and Pubertal Endpoints

AGD and corresponding body weight (for covariate analyses) were recorded for each F_1_ and F_2_ pup on PND 1 (PND 1 is the day after parturition is completed). AGD was measured using a stereomicroscope with a calibrated ocular reticle by a limited number of individuals that demonstrated uniformity and consistency of measurements. The distance between the midpoint of the anal opening to the caudal edge of the genital papilla was recorded and converted to millimeters (mm). F_1_ and F_2_ male pups were evaluated for retention of areolae/nipples on PND 13 and observed for testicular descent over 25 (F_1_) or 28 (F_2_) days beginning on PND 14. Acquisition of balanopreputial separation (BPS), defined as complete retraction of the prepuce from the glans penis, was evaluated in all F_1_ males over 59 days beginning on PND 35, and body weight was recorded upon BPS acquisition. External genitalia were examined for malformations and undescended testes (cryptorchidism). The acquisition of vaginal opening (VO) was evaluated in F_1_ females over 48 days beginning on PND 23, and the corresponding body weight recorded upon VO acquisition.

#### Vaginal Cytology

Beginning on PND 75, vaginal lavages were collected from the F_1_ females in the prenatal and reproductive performance cohorts for 16 consecutive days for evaluation of estrous cyclicity and confirmation of mating. Vaginal vaults were moistened with saline, if necessary, and samples of vaginal fluid and cells were spotted onto a slide and stained with toluidine blue. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stages (diestrus, proestrus, estrus, and metestrus).^61^

#### F_1_ Cohabitation and Assessment of Mating

Sexually mature F_1_ animals in the prenatal (14–15 weeks; 1 male and 1 female/litter) and reproductive performance (17–18 weeks; 2 males and 2 females/litter) cohorts were randomly assigned a mating partner, avoiding sibling pairings, and paired in a 1:1 ratio for up to 15 days. Mating was confirmed by daily examination for the presence of a vaginal copulation plug or sperm in a vaginal lavage. The day of confirmed mating was considered GD 0. Females that did not exhibit evidence of mating or did not deliver a litter were necropsied 25 days after the cohabitation period ended. The uterus was examined grossly and stained with ammonium sulfide to identify potential implantation sites. The number of corpora lutea on the ovary were enumerated, and gross lesions were examined for histopathological changes.

#### Prenatal Cohort

On GD 21, F_2_ fetuses were removed from the uterus, individually weighed (live fetuses only), and examined externally for alterations, including inspection of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were subsequently euthanized by oral administration of sodium pentobarbital. F_1_ females with no evidence of mating were necropsied and examined for gross lesions, which were retained and examined histologically. Fetal sex was confirmed by inspection of gonads in situ. All F_2_ fetuses were examined for soft tissue alterations under a stereomicroscope.^62,63^ The heads were removed from approximately half of the fetuses in each litter, fixed in Bouin’s solution, and subsequently examined by freehand sectioning.^64^ This technique precludes skeletal evaluations of the skull; therefore, remaining heads and all fetuses were eviscerated, fixed in ethanol, macerated in potassium hydroxide, stained with Alcian blue and Alizarin red, and examined for subsequent cartilage and osseous alterations.^65,66^ External, visceral, and skeletal fetal findings were recorded as developmental variations or malformations. After positive evidence of mating, male sires were necropsied, selected organs were weighed, and gross lesions were collected for potential histological examination.

#### Reproductive Performance Cohort

Fertility and fecundity were assessed in two males and two females from each F_1_ litter and all exposure groups. Pup viability was assessed daily during lactation. F_2_ offspring were standardized to a litter size of 8 pups (4/sex/litter, when possible) on PND 4. F_1_ males were euthanized at approximately 22 weeks of age after assessment of fertility, fecundity, and F_2_ generation pup survival. The F_1_ females and the F_2_ offspring were euthanized on PND 28, when the F_1_ females were 18–24 weeks of age. F_2_ offspring were given a gross necropsy. F_1_ sires were necropsied after mating, selected organs were weighed, and gross lesions were collected for potential histological examination. Given the absence of functional changes, a crossover mating to determine affected sex was deemed unnecessary.

Immediately after euthanasia, the left testis and epididymis were removed, trimmed, and weighed. The cauda epididymis was then weighed, and samples were collected for determining cauda epididymal sperm motility, number, and density via automated sperm analyzer (Hamilton Thorne, Inc., Beverly, MA). The sampled left cauda epididymis and the intact corpus and caput were frozen at −80°C for subsequent determination of epididymal sperm concentration from the left cauda epididymis. The left testis was frozen at −80°C for subsequent determination of homogenization-resistant spermatid head counts for calculations of daily sperm production and efficiency of daily sperm production.^67^ The right testis and epididymis were examined histologically. Gross lesions took precedence over sperm parameter assessments (i.e., if the left testis was grossly abnormal, it and the left epididymis would be examined histologically, and the right testis and epididymis, if grossly normal, would be subjected to sperm assessments).

#### Biological Sampling Cohort

On PND 28 and PND 56 (5/sex/time point/exposure group), kidneys, epididymides, testes, ovaries, and liver were collected and frozen for potential future analyses. Plasma samples were also collected from these rats on PNDs 28 and 56 (5/sex/time point/exposure group) and analyzed for 2H4MBP and metabolites.^68^

#### Necropsy and Histopathology

Complete necropsies were performed on adult F_1_ males and F_1_ females in the reproductive performance cohort; unscheduled deaths, F_0_ females, F_1_ males, and F_1_ females in the prenatal cohort; F_1_ females in the reproductive performance cohort that either had no evidence of mating or did not produce a litter; and F_2_ offspring. All gross lesions were examined histologically. In addition, several protocol-required tissues were examined microscopically from the adult F_1_ males and females in the reproductive performance cohorts.

The initial histological examination was performed by an experienced, board-certified veterinary pathologist. The slides, individual animal data records, and pathology tables were subsequently evaluated by an independent quality assessment (QA) laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. A QA pathologist evaluated selected slides from the various cohorts. Kidney histopathology was reviewed from all males and females in the F_1_ reproductive performance cohort and from animals in other cohorts in which the kidney had gross lesions. The urinary bladder, thyroid gland, liver, testis, epididymis, and ovaries were reviewed from all animals in the F_1_ reproductive performance cohort for which the tissue had been previously examined by the study laboratory pathologist.

The QA report and the reviewed slides were submitted to the NTP pathologist, who reviewed and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologist. The QA pathologist, who served as the coordinator of the Pathology Working Group (PWG), presented representative histopathology slides containing examples of lesions related to test article administration, examples of disagreements in diagnoses between the laboratory and QA pathologist, or lesions of general interest to the PWG for review. The PWG consisted of the NTP pathologist and other pathologists experienced in rodent toxicological pathology. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, QA pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^69^ and Boorman et al.^70^

## Statistical Methods

Statistical methods were chosen based on distributional assumptions as well as on the need to incorporate within-litter correlation among animals. Unless specifically mentioned, all endpoints were tested for a trend across exposure groups, followed by pairwise tests for each exposed group against the negative control group. Significance of all trend and pairwise tests is reported at both 0.05 and 0.01 levels.

In the main study, the positive control (EE) was analyzed only by a single pairwise comparison to the negative control. The positive control analysis was kept separate from that of the other exposed groups and was excluded from all trend tests.

### Analysis of Fetal Malformations and Variations

Incidences of malformations and variations in the fetuses were summarized as number of litters affected and as number of fetuses affected. Trend and pairwise analyses of the fetal malformations and variations was conducted using a Cochran-Armitage test with a Rao-Scott adjustment, as described below.

The tendency of fetuses from the same litter to respond more similarly than fetuses from different litters has been referred to as the “litter effect”^71^ and reflects littermates’ similarities in genetics and in utero experiences. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Therefore, the Cochran-Armitage test was modified to accommodate litter effects using the Rao-Scott approach.^72^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Cochran-Armitage test as recommended by Fung et al.,^73^ formula ₸_RS2_.

### Analysis of Incidences of Gross Pathology and Morphology Findings

For the F_0_ dams, incidences of gross findings and histopathology were summarized as number of animals affected. Because some of these animals did not survive until the removal day for their cohort, analysis of the histopathological findings was conducted using the Poly-3 test, as described below.

The Poly-k test^74-76^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage trend test to account for survival differences. Following Bailer and Portier,^74^ a value of k = 3 was used in the analysis of site-specific lesions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^77^ Poly-3 tests used the continuity correction described by Nam.^78^

For the F_1_ and F_2_ animals, incidences of gross findings and histopathology were summarized as number of litters affected and number of animals affected. To account for within-litter correlation, the Rao-Scott adjustment (as described earlier) was applied to the Cochran-Armitage test in the analysis of this data. For histopathological data in F_1_ cohorts in which survival issues could apply, the Poly-3 correction was also applied.

All p values calculated for gross pathological and histopathological data are one-sided and include a continuity correction.

### Analysis of Continuous Endpoints

Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey^79^ for small samples (n < 20) and Tukey’s outer fences method^80^ for large samples (n ≥ 20) were examined by NTP personnel, and implausible values were eliminated from the analysis.

In some instances, no considerations for litter effects were necessary in the analysis of the continuous data. This was the case for the F_0_ generation and for the F_1_ prenatal cohort for which there was only one animal per litter. In these instances, organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^81^ and Williams.^82,83^

When litter effects were present, organ and body weight endpoints were analyzed using linear mixed models, with litters as a random effect. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^84^ Pup and fetal weights were adjusted for litter size by covariate analysis (see below) before analysis. AGD was adjusted for the body weight of the pup taken on the day of AGD measurement. The adjusted AGDs were analyzed as normal variates with litter effects using a linear mixed model.

Feed consumption, litter sizes, pup survival, implantations, number of resorptions, uterine content endpoints, spermatid, and epididymal spermatozoal measurements typically have skewed distributions. When litter effects were not present, these endpoints were analyzed using the nonparametric multiple comparison methods of Shirley^85^ (as modified by Williams^86^ and Dunn^87^). For these endpoints, the Jonckheere test^88^ was used to assess the significance of the exposure concentration-related trends and to determine, at the 0.01 level of significance, whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test).

When litter effects were present for non-normally distributed continuous endpoints, the trend across exposure groups was analyzed by a permutation test based on the Jonckheere trend test implemented by randomly permuting whole litters across exposure groups and bootstrapping within the litters (see, for example, Davison and Hinckley^89^). Pairwise comparisons were made using a modified Wilcoxon test that incorporated litter effects.^90^ The Hommel procedure was used to adjust for multiple comparisons.^91^

### Analysis of Feed Consumption Data

Feed consumption was measured at 3-day intervals for F_0_ and F_1_ dams during gestation and lactation and at least weekly thereafter. In some cases, consumption is reported over intervals that span multiple measurements (e.g., GD 6–21 and LD 1–14). These long-interval values are calculated at the animal or cage level using a weighted average of available constituent subinterval measurements, which are weighted by the underlying subinterval lengths. When spillage is noted or an outlier value is removed from the analysis, the subinterval value for the animal is not reported, and the long interval is calculated excluding that subinterval. As a result, there may be instances in which more animals are reported for a long interval (e.g., GD 6–21) than are reported for the constituent subintervals (GD 6–9, GD 9–12, etc.).

### Analysis of Gestational and Fertility Indices

When litter effects were not present, Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across exposure groups. Fisher’s exact test was used to conduct pairwise comparisons of each exposed group with the control group. P values for these analyses are two-sided.

When litter effects were present, as with the F_1_ reproductive performance cohort, the gestational and fertility indices were tested using the Rao-Scott adjustment to the Cochran-Armitage test. This practice was used for both the trend and pairwise tests.

### Body Weight Adjustments

Because body weights typically decrease with increasing litter size, adjusting body weight for litter size in the analysis of fetal and pup weights can provide additional precision to detect test article effects.^92^ Body weight adjustments are appropriate when the litter effect, as evidenced by decreasing weights with increasing litter size, is relatively constant across exposure concentrations. Adjusted fetal weights were calculated by fitting a linear model to litter mean fetal weights as a function of litter size and exposure concentration, and the estimated coefficient of litter size was then used to adjust each litter mean fetal weight based on the difference between its litter size and the mean litter size. Preweaning pup body weights were adjusted for live litter size as follows. A linear model was fit to body weights as a function of exposure concentration and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight based on the difference between its litter size and the mean litter size. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 21 were adjusted for PND 4 poststandardization litter size. After adjustment, mean body weights were analyzed with a linear mixed model with a random litter effect.

### Analysis of Time-to-event Data

Time-to-event endpoints, such as day of attainment of testicular descent, BPS, and VO, have four features that require careful model selection: (1) they might display non-normality; (2) litter-based correlation might be present; (3) values might be censored, meaning attainment is not observed before the end of the observation period; and (4) growth retardation, reflected in the weaning weight, is an important covariate in the case of BPS and VO given the relationship between normal day of expected attainment and body weight.

For this study, attainment times were approximately normally distributed, and attainment was observed in all but three animals (from the same litter, BPS only). Under these circumstances, a mixed model approach is appropriate. The mixed model used here was fit to attainment day as a function of exposure concentration, as well as a function of both exposure concentration and weaning weight (for BPS and VO) with a random litter effect.

To calculate mean attainment values adjusted for weaning weight, a linear model was fit to attainment day as a function of exposure concentration and weaning weight. The estimated coefficient of weaning weight was then used to adjust each attainment day based on the difference between the measured weaning weight and the mean weaning weight.

Cumulative response percentage, obtained using the methods of Kaplan-Meier,^93^ was plotted against time to attainment for unadjusted attainment times as well as attainment times adjusted for weaning weight. For litter-based plots, the litter median was used as time to attainment if >50% of the pups for that litter attained. Otherwise, litters with ≤50% of the pups attaining had time to attainment set to the final day of observation. These litters are included in the denominator of Kaplan-Meier calculations but not the numerator.

### Analysis of Vaginal Cytology Data

Vaginal cytology data consist of daily observations of estrous cycle stages over a 16-day period. Differences from the control group for cycle length and number of cycles were analyzed using a Datta-Satten modified Wilcoxon test with a Hommel adjustment for multiple comparisons.

To identify disruptions in estrous cyclicity, a continuous-time Markov chain model (multi-state model) was fit using a maximum likelihood approach,^94^ producing estimates of stage lengths for each exposure concentration group. Confidence intervals for these estimates were obtained based on bootstrap sampling of the individual animal cycle sequences. Stage lengths that were significantly different than the control group were identified using permutation testing with a Hommel adjustment.

### Historical Control Data

The concurrent control group is the most valid comparison to the exposed groups and is the only control group analyzed statistically in NTP developmental and reproductive toxicity studies. However, historical control data are often helpful in interpreting potential exposure concentration-related effects, particularly for uncommon fetal findings that occur at a very low incidence. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Factors that might affect the background incidences of fetal findings at a variety of sites are diet, strain/stock, route of exposure, study type, and/or laboratory that conducted the study. The NTP historical control database for fetal findings contains all fetal evaluations from teratology studies and/or modified one-generation studies for each laboratory. In general, the historical control database for a given study includes studies using the same route of administration and study design. However, historical control data for rats in this NTP Developmental and Reproductive Toxicity Technical Report contain data from feed and gavage (all routes) studies conducted at RTI International. The concurrent controls are included in the historical control data set. NTP historical controls are available online at https://ntp.niehs.nih.gov/data/controls/index.html.

## Quality Assurance Methods

This study was conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations, Title 21 of the United States Code of Federal Regulations Part 58.^95^ In addition, this study was audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Developmental and Reproductive Toxicity Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.