# Introduction

Figure 1

2-Hydroxy-4-methoxybenzophenone (CASRN 131-57-7; Chemical Formula: C_14_H_12_O_3_; Molecular Weight: 228.25)

Synonyms: benzophenone-3; (2-hydroxy-4-methoxyphenyl)-phenylmethanoneoxybenzone; oxybenzone.

## Chemical and Physical Properties

2-Hydroxy-4-methoxybenzophenone (2H4MBP) is an off-white to light-yellow powder with a melting point of 62°C to 65°C (Figure 1). 2H4MBP is relatively insoluble in water (69 mg/kg at 25°C) and is readily soluble in most organic solvents. 2H4MBP absorbs ultraviolet (UV) A (320–400 nm) and UVB (290–320 nm) light and is photostable.^1^

## Production, Use, and Human Exposure

2H4MBP is synthesized by condensation of benzoic acid with resorcinol monomethyl ether in the presence of heat, zinc chloride, and polyphosphoric acid or by the Friedel-Crafts reaction of benzoyl chloride with 3-hydroxyanisole.^2^

2H4MBP is commonly used in sunscreens and other personal care products at concentrations of up to 6% to protect the user from solar erythema. According to the Environmental Working Group’s Guide to Sunscreens database,^3^ 2H4MBP is found in more than 1,000 products, including beach, sport, and baby sunscreens (619), moisturizers with SPF (150), and lip balms (109). 2H4MBP is also used as a photostabilizer for synthetic resins and polymers to prevent UV degradation.^4,5^ Exposure can occur when present in acrylic and modified acrylic plastics that come into contact with food.^6^

2H4MBP and its metabolites are typically excreted in urine. A study using National Health and Nutrition Examination Survey (NHANES) cycle data from 2004 to 2012 demonstrated that more than 96% of the 10,232 samples (representing all populations) contained measurable urinary concentrations of 2H4MBP. Creatinine-adjusted urinary least square geometric mean concentrations ranged from 9 to 17 ng/mL in males, and from 18 to 45 ng/mL in females. Children and adolescent concentrations ranged from 17 to 27 ng/mL and from 13 to 24 ng/mL, respectively.^7,8^ Higher urinary concentrations of 2H4MBP were observed in non-Hispanic whites (28 ng/mL) than in Mexican Americans (17 ng/mL) or non-Hispanic blacks (13 ng/mL) and have been attributed to increased sunscreen use.^9^ Higher urinary concentrations in females have been ascribed to the use of personal care products (e.g., lip balms, cosmetics) that often contain 2H4MBP.^9^

## Regulatory Status

2H4MBP is approved by the U.S. Food and Drug Administration (FDA) for use as a sunscreen when present up to 6%, either alone or in combination formulations and as an indirect food additive present in acrylic and modified acrylic plastics that come into contact with food.^6,10^ Section 8(a) of the Toxic Substances Control Act requires manufacturers of 2H4MBP to report preliminary assessment information concerned with production, exposure, and use to the U.S. Environmental Protection Agency (EPA). The FDA has drafted a proposed rule, “Sunscreen Drug Products for Over-the-Counter Human Use.”^10^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

2H4MBP was well absorbed (≥63.9%) following a single oral gavage administration of [^14^C]2H4MBP (3.01–2,570 mg/kg body weight) in male Fischer 344 (F344)/N rats, with the administered dose excreted primarily via urine (63.9% to 72.9%) and feces (19.3% to 41.7%) by 72 hours postadministration. The radioactivity remaining in tissues 72 hours after administration was low (approximately 0.1%) in all dose groups.^11^ Following dermal application of 51.6, 204, and 800 μg [^14^C]2H4MBP (in ethanol) to male rats, the dose was excreted mainly via urine (32.4%, 39.2%, and 13.2%, respectively) and feces (16.9%, 22.2%, and 9.15%, respectively) by 72 hours after application. The dose excreted in urine and feces suggests that the applied dose absorbed was 49.3%, 61.4%, and 22.4%, respectively, for 51.6, 204, and 800 μg [^14^C]2H4MBP. When the dose (50 μg) was applied dermally in a lotion vehicle, the dose absorbed (51.8%) was similar to that in ethanol with 33.9% and 17.9% of the dose recovered in urine and feces, respectively.^11^

Absorption, distribution, metabolism, and excretion (ADME) were also investigated in male and female Sprague Dawley rats and B6C3F1/N mice following gavage administration of [^14^C]2H4MBP.^12^ Following a single gavage administration (10, 100, or 500 mg/kg [^14^C]2H4MBP) in rats, most of the administered dose was excreted in urine (53% to 58%) and feces (25% to 42%) by 72 hours postadministration with no observable sex difference in excretion. The radioactivity in urine suggests that ≥53% of the administered dose was absorbed. Following a single 100 mg/kg gavage dose in male mice, urinary (≥34%) and fecal (≥24%) excretion was similar to that of rats. Mice excreted a higher percentage (5% to 15%) of the administered dose as exhaled CO_2_, however, compared to rats (approximately 1%). The retention of dose in tissues was low at 72 hours (<1%) in all gavage groups.

ADME of 2H4MBP was investigated in Sprague Dawley rats and B6C3F1/N mice at 72 hours following dermal application of 0.1 or 10 mg/kg [^14^C]2H4MBP formulated in several vehicles.^12^ In male rats, the highest absorption was observed following application in light paraffin oil (80%). Absorption following application in ethanol, ethanol:coconut oil (1:1), or coconut oil alone was comparable to paraffin oil (64% to 73%). In contrast, the absorption of 2H4MBP from the lotion vehicle (olive oil:emulsifying wax:water [15:15:70 v:v:v]) in male (10 mg/kg, 46%) and female (15 mg/kg, 29%) rats was lower relative to other vehicles. Both male and female mice absorbed approximately 60%–69% of the 10 mg/kg dose in ethanol or acetone and 37%–46% of the 10 mg/kg dose when formulated in the lotion vehicle. There was no dose-related effect on absorption (0.1 versus 10 mg/kg) in either male rats or mice.^12^

Kinetics of disposition of 2H4MBP have been investigated in rats in limited studies. Following a single gavage dose of 100 mg/kg 2H4MBP in male Sprague Dawley rats, the time (T_max_) to reach the maximum plasma concentration, C_max_ (21.21 μg/mL) was 3 hours; the elimination of 2H4MBP in plasma was biphasic with alpha and beta half-lives of 0.88 and 15.9 hours, respectively. Of the tissues examined, the liver had the highest concentration of 2H4MBP and conjugated 2H4MBP at 6 hours.^13^ In another study, following a 100 mg/kg gavage dose in male Sprague Dawley rats, similar plasma T_max_ (2.72 hours) and C_max_ (21.21 μg/mL) were observed, with an elimination half-life of 4.58 hours.^14^ Following a single gavage dose of 10 mg/kg in male and female Sprague Dawley rats, plasma T_max_ and C_max_ were 6.0 hours and 8.5 ng/mL, respectively, for males and 2.3 hours and 2.9 ng/mL, respectively, for females. The plasma elimination half-life was 6.4 hours for males and 18.5 hours for females. The bioavailability of 2H4MBP in male and female rats was <1%, demonstrating extensive first-pass metabolism of 2H4MBP following gavage administration.^12^

Consistent with low bioavailability, 2H4MBP is metabolized via numerous pathways in rodents, including demethylation, oxidation, glucuronidation, and sulfation. Products identified in bile and/or urine of rodents following administration of 2H4MBP were 2H4MBP, 2,4-dihydroxybenzophenone (DHB), 2,3,4-trihydroxybenzophenone (THB), 2,5-dihydroxy-4-methoxybenzophenone (D2H4MBP), and their corresponding glucuronide and sulfate conjugates (Figure 2).^11-13,15^ Similar metabolites were also observed in vitro following incubation of 2H4MBP with microsomes.^16,17^ 2H4MBP and DHB have been quantified in serum from pregnant rats.^18^

Figure 2

Metabolism of 2-Hydroxy-4-methoxybenzophenone in Rodents

2H4MBP = 2-hydroxy-4-methoxybenzophenone; D2H4MBP = 2,5-dihydroxy-4-methoxybenzophenone; THB = trihydroxybenzophenone; DHB = dihydroxybenzophenone.

*Indicates glucuronide and sulfate conjugates.

### Humans

ADME data on 2H4MBP in humans are limited. Human studies with sunscreens have demonstrated that 2H4MBP is readily absorbed from the skin.^19^ A study that used excised human epidermis in Franz diffusion cells showed that approximately 10% of the dermally applied dose of 2H4MBP is absorbed.^20^ When applied dermally, 2H4MBP and the metabolites DHB and 2,2’-dihydroxy-4-methoxybenzophenone can be detected in serum and are excreted in urine.^21,22^ A study examining the absorption of 2H4MBP and subsequent irradiation with UVA and UVB rays demonstrated that participants excreted 1.2%–8.7% (mean 3.7%) of the total applied dose in urine. 2H4MBP was detected in urine 3–5 days after application. UV irradiation did not affect the amount of 2H4MBP excreted.^23^ Frequency of sunscreen use is also related to urinary 2H4MBP concentrations, with frequent users having much higher urinary concentrations.^24^ 2H4MBP has been detected in maternal urine^25^ and breast milk.^26,27^ Human geometric mean maximum plasma concentrations of 2H4MBP have been shown to be approximately 200 ng/mL when topically applied. This concentration exceeds the FDA guidance of 0.5 ng/mL that would necessitate the conduct of additional nonclinical toxicity studies.^28^

## Developmental and Reproductive Toxicity

### Models of Endocrine Activity

2H4MBP has been reported to bind to and activate estrogen receptor (ER) alpha (ERα) with a median effective concentration (EC_50_) ranging from approximately 3 to 20 μM.^29-32^ 2H4MBP can also activate estrogen receptor beta (ERβ),^31,33^ and reports indicate that 2H4MBP can act as ERα, ERβ, and progesterone receptor antagonists.^31-33^ In NTP-sponsored ER binding and activation studies^34^ conducted under OPPTS^a^ 890.1250^35^ and OPPTS 890.1300,^36^ maximal mean specific binding was >75%, which categorizes 2H4MBP as “not interactive”; however, 2H4MBP was able to induce a luciferase response, albeit weak (>10%; logEC_50_s of −3.2 and −4.0 M). 2H4MBP acts as an estrogen in stimulating MCF7 cell proliferation (EC_50_ of 3.7 × 10^-6^ M). 2H4MBP has been shown to induce a uterotrophic response (median effective dose [ED_50_] of 1,000–1,500 mg/kg per day) in immature rats,^37^ but 2H4MBP did not cause a uterotrophic response in ovariectomized rats when tested ≤1 g/kg in an NTP study.^34^ 2H4MBP was evaluated in quantitative (dose-response) high-throughput screening assays by NTP in the Toxicology in the 21^st^ Century (Tox21) program, and activity was observed in assays measuring stimulation of ER, progesterone receptor, constitutive androstane receptor, pregnane X receptor, retinoic acid receptor, and estrogen-related receptor signaling pathways. In addition, 2H4MBP was shown to inhibit androgen-receptor signaling (https://pubchem.ncbi.nlm.nih.gov/compound/4632#section=BioAssay-Results&fullscreen=true).

a Guidelines issued before April 22, 2010, refer to “OPPTS” because the office name changed from “Office of Prevention, Pesticides and Toxic Substances” to “Office of Chemical Safety and Pollution Prevention” (or “OCSPP”).

2H4MBP exposure in male rainbow trout and Japanese medaka has been shown to induce vitellogenin production (an estrogenic response), decrease the number of eggs produced, and reduce egg viability and hatching.^38^ 2H4MBP has also been shown to increase plasma concentrations of testosterone in male adult Japanese medaka and to decrease the estradiol-to-testosterone ratio in both male and female fish with concomitant downregulation of gonadal steroidogenic genes (star, cyp11a, cyp17, hsd3b, hsd17b3, and cyp19a).^39^

### Experimental Animals

The effects of 2H4MBP exposure on sperm density and vaginal cytology have been reported.^40^ Rats and mice received 0, 3,125, 6,250,12,500, 25,000, or 50,000 ppm in the diet for 90 days (approximately 200, 410, 830, 1,700, 3,460 and 550, 1,250, 2,860, 6,780, 16,240 mg/kg/day, respectively). Male rats exposed to 50,000 ppm weighed 30% less than control animals, displayed lower epididymis and caudal epididymis weights (17% and 22%, respectively), and lower sperm density (27%). Females displayed a slight increase in estrous cycle length (>1 day) in the 12,500 and 50,000 ppm groups. Male mice in the 50,000 ppm group displayed a 27% decrease in sperm density and weighed 16% less than control animals. Female mice in the 50,000 ppm group displayed a slight increase in estrous cycle length relative to control animals (>0.5 days). NTP conducted a Reproductive Assessment by Continuous Breeding (RACB) study in mice at exposure concentrations of 12,500, 25,000, or 50,000 ppm in the diet.^41^ 2H4MBP exposure had no effect on F_0_ fertility, but the number of live pups per litter was significantly reduced in the 25,000 and 50,000 ppm groups, which was associated with lower parental mean body weights. There were no changes in sperm density or estrous cyclicity; however, the cumulative days to litter were increased in the 50,000 ppm group. 2H4MBP had minimal effects on fertility in the F_1_ generation, but pup weights were significantly decreased relative to the control group. Collectively, the studies indicated that 2H4MBP caused systemic toxicity but had minimal effects on fertility and reproduction at the exposure concentrations used. Another study examined the effects of 0, 10, 20, 100, or 400 mg/kg of 2H4MBP dermally applied to mice 5 days per week for 13 weeks. No effects on mean body weight, organ weights, sperm density, or testicular histopathology were attributed to 2H4MBP exposure.^42^

The effects of maternal and lactational exposure to 2H4MBP on F_1_ development and reproductive organs have been assessed.^18^ Rats received 0, 1,000, 3,000, 10,000, 25,000, or 50,000 ppm 2H4MBP in the diet from gestation day (GD) 6 until weaning on postnatal day (PND) 23. Exposure to 2H4MBP was associated with increased liver and kidney weights in dams. Clinical pathology findings in dams assessed on GDs 10, 15, and 20 and lactation day 23 included elevation of glucose, alanine aminotransferase, alkaline phosphatase, cholesterol, and total bile acids, as well as depression of aspartate aminotransferase, blood urea nitrogen, and creatinine. These findings occurred primarily in the higher dosed groups and often at all time points. Alanine aminotransferase and cholesterol were elevated in the male and female offspring at the 25,000 and 50,000 ppm exposure concentrations. No significant differences were observed in littering parameters. Male and female pups in the 25,000 and 50,000 ppm groups displayed lower body weights than control pups. Male anogenital distance, adjusted for body weight at PND 23, was significantly decreased in the 50,000 ppm group relative to the control group. At necropsy on PND 23, relative female liver weights were higher than those of the control group at exposure concentrations ≥10,000 ppm. In the 50,000 ppm group, spermatocyte development was impaired and ovarian follicular development was delayed.

#### Endocrine Disruptor Screening Panel Studies

The potential for 2H4MBP to bind to the ER was assessed in accordance with EPA guideline OPPTS 890.1250.^35^ In each of three independent experiments, the maximal mean specific binding was >75% at every soluble 2H4MBP concentration assessed, thereby categorizing 2H4MBP as “not interactive.” When the specific binding was averaged using the scoring system as described in the OPPTS guideline, 2H4MBP was classified as “not interactive” with a median inhibitory concentration (IC_50_) of approximately 2.3 × 10^-4^ to 14.8 × 10^-4^ M. In the ER transcriptional activation assay, conducted in accordance with EPA guideline OPPTS 890.1300,^36^ 2H4MBP at 10^−5^ M induced relative luciferase activity of 14.9% and 20.9% in each respective run. 2H4MBP was considered a “positive” agent, per OPPTS 890.1300, because it exceeded 10% of the response of the positive control. 2H4MBP was assessed in a uterotrophic assay in accordance with OPPTS 890.1600,^43^ and 2H4MBP did not significantly alter uterine wet or blotted weights.^34^

The potential for 2H4MBP to bind to the rat androgen receptor was assessed in accordance with OPPTS 890.1150.^44^ 2H4MBP tested up to 10^−4^ M did not displace more than 50% of the [^3^H]-R1881, a synthetic androgen-receptor agonist, categorizing 2H4MBP as “equivocal.” The potential for 2H4MBP to induce androgenic agonist and antagonist transactivation activity was assessed in MDA-kb2 reporter cells that had been stably transfected with a mouse mammary tumor virus luciferase-neo reporter construct containing the androgen response element. In all independent runs of the agonist transcriptional activation assay, 2H4MBP did not increase luciferase activity at any of the viable soluble concentrations tested. In two of three runs, the decrease in dihydrotestosterone-induced luciferase activity resulting from 2H4MBP exposure was approximately 25% at the highest feasible dose of 10^−4.5^ M, with the first run exhibiting a luciferase activity of 72.2% of maximal. The potential for 2H4MBP to have an androgenic or antiandrogenic response was assessed in a Hershberger bioassay conducted in accordance with OPPTS 890.1400.^45^ In the absence of androgenic action, 2H4MBP up to 1,000 mg/kg did not have any effect on androgen-dependent organ weights, demonstrating that 2H4MBP does not exhibit any in vivo androgenic activity in this model system. Rats co-administered 1,000 mg/kg of 2H4MBP and testosterone propionate displayed significantly decreased day 10 mean body weight and body weight gain (7% and 28%, respectively) relative to the control group. The mean weights of the glans penis and ventral prostate were also significantly decreased (6% and 20%, respectively). The weight of the seminal vesicles was also significantly decreased; however, when concurrent body weight is used as a covariate, the magnitude of the response is lower and no longer attains statistical significance. The observation that these organ weight changes only occurred in the presence of lower body weights at the highest dose assessed suggests that they could be secondary to effects on body weight.^34^

The potential for 2H4MBP to act as an inhibitor of aromatase activity was assessed using human CYP19 (aromatase) and P450 reductase Supersomes^TM^ 2H4MBP in accordance with OPPTS 890.1200.^46^ 2H4MBP was classified as equivocal, as it produced a mean aromatase activity level of 51% (±13% SD) of control activity at the highest soluble test concentration of 10^−4^ M.^34^

### Humans

Maternal 2H4MBP exposure, determined primarily via third trimester urinary concentrations, was associated with lower birth weight of girls and higher birth weight of boys.^47^ In another study, maternal gestational urinary 2H4MBP concentrations were positively associated with weight and head circumference at birth in male newborns.^48^ Maternal exposure to 2H4MBP has been postulated to be involved in the development of Hirschsprung’s disease. One hypothesis is that this complex congenital disease is caused by gene–environment interactions that can lead to intestinal obstruction and chronic constipation in the offspring.^49^ Pregnant women who had higher 2H4MBP concentrations in urine exhibited higher odds (2.4 to 2.6:1) of having a child with Hirschsprung’s disease.^25^ In the 293T and SH-SY5Y cell migration model of Hirschsprung’s disease, 2H4MBP suppressed migration and altered the levels of key migratory proteins at both the ribonucleic acid and transcribed protein levels in the absence of cytotoxicity.^25,49^

A study looking at the potential effect of 2H4MBP dermal application and serum hormone changes in young men and postmenopausal women concluded that the amount of 2H4MBP absorbed did not alter the endogenous reproductive hormone homeostasis.^19^

## General Toxicity

### Experimental Animals

The acute rat dermal median lethal dose (LD_50_) has been reported to be >16 g/kg. Concomitant local skin reactions consisting of mild to moderate erythema were observed in the absence of significant pathological findings.^5^ The acute rat oral LD_50_ for 2H4MBP has been reported to be >12.8 g/kg.^50^ These authors also reported that administration of 0.5% or 1% 2H4MBP in rat diet for 12 weeks was associated with growth depression. Upon examination at week 6, female rats exposed to 0.5% or 1% displayed a leukocytosis with an increase in the lymphocyte count and a decrease in the neutrophil count, as well as a decrease in hemoglobin concentration compared to control females. At week 12, exposed rats displayed anemia and lymphocytosis with a reduction in granulocytes. The relative weights of the pituitary gland, thymus, heart, adrenal gland, lung, and spleen were also lower in both sexes. The 0.5% females showed higher relative thyroid weight than the control group, as well as the first stages of kidney degeneration. Degenerative nephrosis was diagnosed both macro- and microscopically in the kidneys of both sexes at 1%.

NTP has reported the findings of three studies conducted in F344 rats exposed to: (1) 0, 3,125, 6,250, 12,500, 25,000, or 50,000 ppm 2H4MBP in feed for 2 or 13 weeks; (2) 0, 1.25, 2.5, 5, 10, or 20 mg/kg 5 days per week for 2 weeks dermally in acetone or lotion; and (3) 12.5, 25, 50, 100, or 200 mg/kg in acetone or lotion 5 days per week for 13 weeks.^40^ After dietary administration for 2 weeks, 6,250 ppm 2H4MBP and higher concentrations were associated with higher liver weights and marked hepatocyte cytoplasmic vacuolization. As was observed in the 2-week study, kidney and liver weights were higher in the 2H4MBP-exposed rats in the 13-week study at exposure concentrations of 3,125 ppm and higher (liver) or 25,000 ppm and higher (kidney). Histopathological kidney findings included dilated tubules and tubular epithelial cell regeneration. These findings were observed primarily in high-dosed rats. In the 13-week feed study, 2H4MBP administration was associated with lower body weight gains of 50,000 ppm male and female rats. Additionally, in the 13-week feed study, kidney lesions progressed to include papillary degeneration or necrosis and inflammation. Although cytoplasmic vacuolization was not observed in the liver, liver enzymes remained elevated at 13 weeks. In the 2-week dermal study, small and variable increases in liver and kidney weights were observed in exposed groups, with statistically significant differences observed primarily in the higher dose groups. In the 13-week dermal study, female rats in the higher dose groups displayed higher kidney weights than the control group. No other findings were attributed to 2H4MBP exposure. A 4-week dermal study in rats using 100 mg/kg 2H4MBP in petroleum jelly twice a day did not affect body weight; liver, kidney, or testes weights; or histopathology.^15^ 2H4MBP exposure did lower rat blood glutathione-S-transferase levels.

### Humans

The literature contains no studies on the general toxicity of 2H4MBP in humans.

## Immunotoxicity

### Experimental Animals

A study conducted for irritation per the Draize method concluded that an occlusive patch containing 0.5 mL or 0.5 mg at 2H4MBP concentrations from 4% to 100% was nonirritating to intact and abraded albino rabbit skin.^5^ 2H4MBP at 100% up to 100 mg was found not to be irritating to the rabbit eye using the modified FSLA or Draize methods. A sunscreen containing 6% 2H4MBP was found not to be photosensitizing in albino rabbits and was negative for sensitization potential in the Klingman Maximization Procedure^5^ and local lymph node assay.^51^

### Humans

Some reports have indicated that 2H4MBP might induce allergenic and sensitization responses.^5^ In a sunscreen sensitization study, researchers detected allergy and/or photoallergy in 3.7% of the human subjects, which was attributed to application of moisturizing creams that contained 2H4MBP.^52^ A subsequent study sponsored by Schering-Plough HealthCare Products reported the results of the meta-analysis of 64 unpublished studies conducted at 10 independent clinical laboratories representing the results of 19,570 individuals subjected to human repeat insult patch tests and photoallergy studies between 1992 and 2006.^53^ These studies were aggregated and analyzed to evaluate the irritancy and sensitization potential of sunscreen products containing 2H4MBP concentrations between 1% and 6%. Forty-eight dermal responses were considered suggestive of sensitization or irritation with a mean rate of response of 0.26%. The authors concluded that sunscreen products formulated with 1% to 6% 2H4MBP do not possess a significant sensitization or irritation potential for the general public. 2H4MBP was also negative in an in vitro phototoxicity assay using SkinEthic^™^, a human epidermis model.^54^

## Study Rationale

2H4MBP was nominated to NTP by the National Cancer Institute because of high exposure via use of 2H4MBP-containing sunscreen products and lack of chronic toxicity and carcinogenicity data. 2H4MBP was also nominated by a private individual to ascertain genotoxic potential. Furthermore, there are concerns about the endocrine activity of 2H4MBP. Under the purview of the Sunscreen Innovation Act of 2014, FDA is in the process of reviewing toxicity data on specific commonly used sunscreens to ascertain whether the available data support a positive GRASE (generally recognized as safe and effective)^55^ designation. FDA is also in the process of finalizing and making effective the Sunscreen Monograph, which will update conditions under which over-the-counter sunscreen products can be marketed in the United States. FDA had expressed concern about the potential long-term adverse effects,^56^ or effects not otherwise readily detected from human use, and specifically identified reproductive toxicity and carcinogenicity as concerns. This concern was elevated due to data in the published literature suggesting potential for endocrine activity.

To understand the potential effects on reproduction and development, NTP conducted this study with continual 2H4MBP exposure in a sensitive animal model to address the potential for 2H4MBP to (1) exhibit endocrine activity, (2) affect the ability of offspring to reproduce, and (3) induce adverse fetal effects. In addition, this study allowed for quantification of 2H4MBP in the blood at different ages for comparison to human blood concentrations. This report complements ICH^b^ S5r2 guideline studies (fertility and early embryonic development, embryo-fetal development, and pre- and postnatal developmental studies in rats) on 2H4MBP^57^ conducted by FDA’s National Center for Toxicological Research, an interagency NTP partner, and allows for the comparison of study designs and outcomes. Potential endocrine activity that could result in neoplastic/tumorigenic responses was assessed in the concurrently conducted mouse and rat 2-year toxicology and carcinogenesis studies. The 2-year rat study also included perinatal exposure.^34^

b ICH = International Council for Harmonisation of Technical Requirements for Pharmaceuticals for Human Use.

As disposition is similar following oral and dermal exposure, 2H4MBP exposure via the diet was selected for this study, rather than topical application, to sustain internal exposure. It was also recognized that if applied topically, internal dose would be influenced by intra- and inter-animal grooming behavior. To minimize the potential endocrine activity of phytoestrogens that are often present in rodent diets, a diet low in phytoestrogens was used. Ethinyl estradiol, a synthetic form of estrogen, was selected as a positive control to provide context for any potential estrogen-like findings in 2H4MBP-exposed rats, if present.