# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For this modified one-generation study, blood samples were collected from each sentinel animal and allowed to clot, and the serum was separated. All samples were processed appropriately with serology testing performed by IDEXX BioAnalytics (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens.

The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed (Table C-1).

Table C-1 Methods and Results for Sentinel Animal Testing in Female Rats

Modified One-Generation Study
Collection Time Points | Quarantine | 1 Month | 16 Weeks | Study Termination
Number Examined (Males/Females)^a^ | 0/5 | 0/5 | 0/5 | 0/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | – | – | – | –
Mycoplasma pulmonis | – | – | – | –
Pneumonia virus of mice (PVM) | – | – | – | –
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | – | – | – | –
Rat minute virus (RMV) | – | – | – | –
Rat parvo virus (RPV) | – | – | – | –
Rat theilovirus (RTV) | – | – | – | –
Sendai | – | – | – | –
Toolan’s H1 | – | – | – | –
Immunofluorescence Assay (IFA)
Pneumocystis carinii | – | NT | NT | NT
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | NT | – | NT | NT

– = negative; NT = not tested.

^a^ Age matched nonpregnant females.

## C.2 Results

All test results were negative.