# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in 5K96 Rat Ration

Additional information on ingredients, vitamins, and minerals in the 5K96 rat diet can be found online.^121^

Table B-1 Nutrient Composition of 5K96 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 21.04 ± 0.6188 | 19.9–21.7 | 7
Crude Fat (% by Weight) | 4.23 ± 0.1604 | 4.0–4.4 | 7
Crude Fiber (% by Weight) | 3.21 ± 0.2260 | 2.95–3.63 | 7
Ash (% by Weight) | 6.73 ± 0.3696 | 6.13–7.20 | 7
Vitamins
Vitamin A (IU/kg) | 18,714 ± 2,918 | 14,800–22,600 | 7
Thiamine (ppm)^a^ | 16.86 ± 1.753 | 14.2–19.8 | 7
Minerals
Calcium (%) | 1.273 ± 0.1316 | 1.18–1.56 | 7
Phosphorus (%) | 0.963 ± 0.0668 | 0.886–1.09 | 7

^a^ As hydrochloride.

Table B-2 Contaminant Levels in 5K96 Rat Ration

Contaminant | Mean ± Standard Deviation | Range | Number of Samples
Arsenic (ppm) | 0.3366 ± 0.0501 | 0.267–0.398 | 7
Cadmium (ppm) | 0.041 ± 0.0041 | 0.0327–0.0457 | 7
Lead (ppm) | 0.2393 ± 0.0122 | 0.224–0.263 | 7
Mercury (ppm) | 0.0106 ± 0.0010 | 0.01–0.0126 | 7
Selenium (ppm) | 0.4451 ± 0.0421 | 0.404–0.53 | 7
Aflatoxins (ppb)^a^ | <2.0 | – | 7
Nitrate Nitrogen (ppm)^b^ | 14.73 ± 10.95 | 1.69–24.6 | 7
Nitrite Nitrogen (ppm)^a,b^ | <1.0 | – | 7
BHA (ppm)^c^ | 0.743 ± 0.4392 | 0.1–1.0 | 7
BHT (ppm)^c^ | 0.793 ± 0.4903 | 0.1–1.35 | 7
Aerobic Plate Count (CFU/g)^d^ | 1,275 ± 2,712 | 10–6,800 | 7
Coliform (MPN/g) | <3.0 | – | 7
Escherichia coli (MPN/g) | <10.0 | – | 7
Enterobacteriaceae (MPN/g) | <3.0 | – | 7
Total Nitrosamines (ppb)^e^ | 9.9 ± 8.4 | 0–24.8 | 7
N-N-dimethylamine (ppb)^e^ | 6.6 ± 6.9 | 0–20.3 | 7
N-N-pyrrolidine (ppb)^e^ | 3.3 ± 2.5 | 0–7.5 | 7
Pesticides (ppm)
α-BHC^a^ | – | – | 7
β-BHC^a^ | – | – | 7
γ-BHC^a^ | – | – | 7
δ-BHC^a^ | – | – | 7
Heptachlor^a^ | – | – | 7
Aldrin^a^ | – | – | 7
Heptachlor Epoxide^a^ | – | – | 7
DDE^a^ | – | – | 7
DDD^a^ | – | – | 7
DDT^a^ | – | – | 7
HCB^a^ | – | – | 7
Mirex^a^ | – | – | 7
Methoxychlor^a^ | – | – | 7
Dieldrin^a^ | – | – | 7
Endrin^a^ | – | – | 7
Telodrin^a^ | – | – | 7
Chlordane^a^ | – | – | 7
Toxaphene^a^ | – | – | 7
Estimated PCBs^a^ | – | – | 7
Ronnel^a^ | – | – | 7
Ethion^a^ | – | – | 7
Trithion^a^ | – | – | 7
Diazinon^a^ | – | – | 7
Methyl Chlorpyrifos | 0 ± 0.02 | 0.02 | 7
Methyl Parathion^a^ | – | – | 7
Ethyl Parathion^a^ | – | – | 7
Malathion | 0 ± 0.02 | 0.02 | 7
Endosulfan I^a^ | – | – | 7
Endosulfan II^a^ | – | – | 7
Endosulfane Sulfate^a^ | – | – | 7

All samples were irradiated. BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ Preirradiation values given.

^e^ All values were corrected for percent recovery.