# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 2-Hydroxy-4-methoxybenzophenone

2-Hydroxy-4-methoxybenzophenone (2H4MBP) was obtained from Ivy Fine Chemicals (Cherry Hill, NJ) in a single lot (20100801), which was used for the dose range-finding and modified one-generation (MOG) studies. Identity, purity, and stability analyses were conducted by the analytical chemistry and study laboratory at Battelle (Columbus, OH). Reports on analysis performed in support of the 2H4MBP studies are on file at the National Institute of Environmental Health Sciences.

Lot 20100801 of the chemical was a light-yellow powder. The lot identity was confirmed using infrared (IR) spectroscopy and ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopy. The IR spectrum (Figure A-1) was in good agreement with the anticipated structure and the reference spectrum (BP #824 from the Sadtler Basic Monomers and Polymers Library [Bio-Rad Laboratories, Hercules, CA]). Reference ^1^H and ^13^C NMR spectra for 2H4MBP were obtained from the National Institute of Advanced Industrial Science and Technology (NIAIST) (Tokyo, Japan) Spectral Database for Organic Compounds (SDBS No. 5800HSP-01-137 and 5800CDS-04-696, respectively). The Advanced Chemistry Development (ACD, Toronto, Canada) HNMR spectral prediction program (Version 12.01) was also used to predict these NMR spectra. Both the ^1^H and ^13^C NMR spectra obtained for lot 20100801 were consistent with these references. Additionally, a ^1^H-^1^H correlated spectroscopy (COSY) two-dimensional spectrum, Distortionless Enhancement by Polarization Transfer (DEPT) ^13^C spectral series, and ^1^H-^13^C heteronuclear multiple quantum coherence (HMQC) two-dimensional spectrum collected for lot 20100801 were in good agreement with the anticipated spectra for 2H4MBP.

The purity of 2H4MBP lot 20080801 was determined using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection, as well as gas chromatography (GC) with flame ionization detection (FID). The HPLC/UV analysis showed a single impurity with a peak area <0.1%, indicating an 2H4MBP purity of approximately 100.0%. The chromatogram obtained from GC/FID consisted of a single major peak consistent with a purity of 100.0%. Lot 20080801 was screened for common residual volatile solvents using GC with electron capture detection (ECD) and FID; no significant volatile impurities were found. Differential scanning calorimetry (DSC) was also used to determine the purity of the test article. Analysis using a PerkinElmer (Shelton, CT) diamond DSC yielded a purity of 99.9% with a melting point of approximately 62°C. In addition, Karl Fisher titration of 2H4MBP lot 20080801 was conducted to estimate moisture content, which was found to be insignificant (<0.5%) in an analysis conducted by Galbraith Laboratories, Inc. (Knoxville, TN). Thus, the overall purity of 2H4MBP lot 20100801 was determined to be >99.9%. Additional details on the chromatography systems used are provided in Table A-1.

Although the entirety of 2H4MBP came from lot 20100801, the chemical was received in eight drums (25 kg each) and not homogenized. Homogeneity analysis conducted on three samples taken during chemical handling using HPLC/UV found that the samples were statistically equivalent to the purity of the standard.

To ensure stability, the test chemical was stored in sealed amber glass bottles at room temperature (approximately 25°C). Periodic analysis of 2H4MBP lot 20100801 by the study laboratory using HPLC/UV showed no degradation of the bulk 2H4MBP chemical prior to and during the animal studies relative to a frozen reference sample.

### A.1.2 Ethinyl Estradiol

Ethinyl estradiol (EE) was obtained in a single lot (090M1241V) from Sigma-Aldrich (St. Louis, MO) via Government Scientific Source, Inc. (Reston, VA). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH).

EE lot 090M1241V was a white powder. The lot identity was confirmed using IR spectroscopy and ^1^H and ^13^C spectroscopy. The IR spectrum (Figure A-2) was consistent with the available reference spectrum in the Sadtler Steroids, Androgens, Progestins, and Estrogens Library (Bio-Rad Laboratories, Hercules, CA). Reference ^1^H and ^13^C NMR spectra for EE were obtained from the NIAIST (Tokyo, Japan) Spectral Database for Organic Compounds. The ACD (Toronto, Canada) spectral prediction program (Version 12.01) was also used to predict these NMR spectra. Both the ^1^H and ^13^C NMR spectra obtained for lot 09M1241V were consistent with these references. Additionally, a ^1^H-^1^H COSY two-dimensional spectrum, DEPT ^13^C spectral series, and ^1^H-^13^C HMQC two-dimensional spectrum collected for lot 09M1241V were in good agreement with the anticipated spectra for EE. Elemental analysis indicated that the sample was approximately 80.4% carbon, 11.5% oxygen, 7.9% hydrogen, and >0.5% nitrogen, which is consistent with theoretical values.

Purity assessment by HPLC/UV showed one impurity with a relative area of 0.23% of the total peak area, indicating an EE purity of 99.8% for lot 090M1241V. Analysis for volatiles using headspace GC/FID found that the sample contained approximately 0.023% acetone; no other volatiles were detected. DSC yielded a purity of 99.7% and a melting point of 184°C. Karl Fischer analysis indicated that the water content of lot 090M1241V was approximately 0.4%. These data indicate that the EE purity of lot 090M1241V was ≥99.7%, consistent with the manufacturer-reported purity of 99%. Additional details on the systems used are provided in Table A-1.

HPLC/UV analysis was used to determine the partition coefficient (log P_ow_) for EE lot 090M1241V, and the average determined log P_ow_ was 1.2, which is approximately one-third of the published log P_ow_ value for EE of 3.7. However, calculation of the log P_ow_ against additional comparison hormones produced a log P_ow_ of 3.8, consistent with the published value.

To ensure stability, the EE positive control was stored in sealed glass containers at room temperature (approximately 25°C). Prior to the study and at study termination, lot 090M1241V was analyzed using HPLC/UV to ensure chemical stability.

## A.2 Preparation and Analysis of Dose Formulations

### A.2.1 2-Hydroxy-4-methoxybenzophenone

Dosed feed formulations were prepared monthly (dose range-finding study) or eight times (MOG study) (Table A-2) using irradiated low-phytoestrogen feed (5K96 Casein diet). Formulations were stored at approximately 5°C for up to 42 days in amber glass bottles. Prior to beginning the study, the homogeneity of 1,000–50,000 ppm 2H4MBP formulations in 5K96 feed was confirmed using HPLC/UV. The analytical chemistry laboratory at Battelle (Columbus, OH) conducted the homogeneity evaluation and all additional dose formulation analysis throughout the study.

Stability analysis was conducted on the 1,000 ppm formulation using HPLC/UV. When sealed and stored in amber plastic bags, the 2H4MBP formulations stored for 42 days at room temperature (approximately 25°C), refrigerated (approximately 5°C), or frozen (−20°C) were within 10% of the day 0 values. There was a slight declining trend in concentration (0.1%–0.2% per day) at all temperatures. To simulate conditions in the animal room, the 1,000 ppm formulation was stored in open glass containers with and without rodent urine and feces for 7 days; no significant loss in 2H4MBP was found when analyzed with HPLC/UV relative to the day 0 values. The preadministration dose formulations were analyzed three times over the course of the study (Table A-3) using HPLC/UV. All preadministration samples were within 10% of the targeted concentration except one 25,000 ppm formulation, which was 15.2% above the target concentration. For one set of dose formulations, postadministration samples were collected from the animal room approximately one month after preparation. These formulations were within 10% of the target dose.

### A.2.2 Ethinyl Estradiol

Dosed feed formulations were prepared eight times (Table A-2) using 5K96 feed. Formulations were stored at −20°C for <57 days in sealed amber plastic bags. The homogeneity of 0.05 ppm EE formulations in 5K96 feed was confirmed before conducting the studies.

Stability analysis conducted on the 0.05 ppm formulation found that it was stable for 57 days when stored in sealed amber plastic bags at −20°C and usable for 57 days when store in sealed amber plastic bags at approximately 5°C and room temperature. An animal room simulation of the 0.05 ppm formulation in open glass containers without rodent urine and feces for 8 days showed formulations were within 10% of the day 0 value; however, when urine and feces were present, a slight decline in EE occurred.

The preadministration dosed feed formulations were analyzed three times over the course of the dose range-finding study (Table A-3) and four times over the course of the MOG study (Table A-4) using HPLC/UV. All preadministration samples were within 10% of the target concentration with the exception of two formulations, one of which was that were 11% below and the other 12% above. Postadministration samples were collected from the animal room at the end of the exposure period and sent to Battelle (Columbus, OH) for analysis. The concentration of the animal room sample was within 10% of the preadministration analyses and, therefore, demonstrated acceptable stability during its use in the study.

Table A-1 Chromatography Systems Used in the Modified One-Generation Study of 2-Hydroxy-4-methoxybenzophenone

Chromatography | Detection System | Column | Mobile Phase
System A
HPLC | UV (289 nm) | Phenomenex, Synergi Fusion RP; 100 × 4.6 mm, 4 μm | 40/60 acetonitrile:ASTM Type I water; flow rate 1.2 mL/min
System B
HPLC | UV (289 nm) | Phenomenex, Synergi Fusion RP; 100 × 3 mm, 2.5 μm | 40/60 acetonitrile:ASTM Type I water; flow rate 0.8 mL/min
System C
HPLC | UV (289 nm) | Phenomenex, Synergi Fusion RP; 100 × 3 mm, 2.5 μm | 40/60 acetonitrile:ASTM Type I water; flow rate 0.8 mL/min
System D
GC | FID | Restek, Rtx-5; 30 m × 0.32 mm, 1.0 μm film thickness | Helium; flow rate of ~3 mL/min
System E
GC | FID; ECD | Restek, Rtx-624; 30 m × 0.53 mm, 3 μm film thickness | Helium; flow rate of ~5 mL/min
System F
HPLC | UV (280 nm) | Phenomenex, Luna; 250 mm × 4.6 mm, 5 μm film thickness | 50/50 acetonitrile:ASTM Type 1 water; flow rate 1.0 μL/min
System G
HPLC | UV (205 nm) | Thermo, BDS Hypersil; 100 mm × 4.6 mm, 3 μm film thickness | 65/35 acetonitrile:ASTM Type 1 water; flow rate 1 mL/min

HPLC = high-performance liquid chromatography; UV = ultraviolet; ASTM = American Society for Testing and Materials; GC = gas chromatography; FID = flame ionization detection; ECD = electron capture detection.

Table A-2 Preparation and Storage of Dose Formulations in the Modified One-Generation Study of 2-Hydroxy-4-methoxybenzophenone

Preparation
Stock solutions of 2H4MBP or EE were prepared by weighing the appropriate amount of lot 20100801 (2H4MBP) or lot 090M1241V (EE) into volumetric flasks and bringing to volume with methanol. Flasks were sealed and mixed well to ensure the test articles thoroughly dissolved. Irradiated 5K96 feed was weighed into amber glass bottles to which stock solution and methanol were added to create the proper 2H4MBP or EE concentration. Bottles were sealed and rotated end-over-end for 30 minutes to ensure homogeneity. Over the course of the study, eight dose formulations were prepared.
Chemical Lot Number
20100801 (2H4MBP) 090M1241V (EE)
Maximum Storage Time
42 days (2H4MBP) 57 days (EE)
Storage Conditions
Stored in sealed amber glass bottles at approximately 5°C (2H4MBP) Stored in sealed amber plastic bags at −20°C (EE)
Study Laboratory
Battelle (Columbus, OH)

2H4MBP = 2-hydroxy-4-methoxybenzophenone; EE = ethinyl estradiol.

Table A-3 Results of Analyses of Dose Formulations Administered to Rats in the Dose Range-finding Study of 2-Hydroxy-4-methoxybenzophenone

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
2H4MBP
June 30, 2011 | July 8–9, 2011 | 3,000 | 3,010 | 0.0
June 30, 2011 | July 8–9, 2011 | 10,000 | 10,100 | 1.0
June 30, 2011 | July 8–9, 2011 | 25,000 | 25,100 | 0.0
June 30, 2011 | July 8–9, 2011 | 50,000 | 51,500 | 3.0
July 21, 2011 | July 27–28, 2011 | 3,000 | 3,030 | 1.0
July 21, 2011 | July 27–28, 2011 | 10,000 | 10,100 | 1.0
July 21, 2011 | July 27–28, 2011 | 25,000 | 25,400 | 2.0
July 21, 2011 | July 27–28, 2011 | 50,000 | 50,400 | 1.0
August 29, 2011 | September 1–2, 2011 | 3,000 | 2,980 | −0.7
August 29, 2011 | September 1–2, 2011 | 10,000 | 9,980 | −0.2
August 29, 2011 | September 1–2, 2011 | 25,000 | 25,600 | 2.0
August 29, 2011 | September 1–2, 2011 | 50,000 | 50,200 | 0.0
Animal Room Samples
June 30, 2011 | August 16–17, 2011 | 3,000 | 2,830 | −5.8
June 30, 2011 | August 16–17, 2011 | 10,000 | 9,840 | −1.6
June 30, 2011 | August 16–17, 2011 | 25,000 | 26,000 | 4.0
June 30, 2011 | August 16–17, 2011 | 50,000 | 49,100 | −1.7
July 21, 2011 | September 7–8, 2011 | 3,000 | 2,870 | −4.3
July 21, 2011 | September 7–8, 2011 | 10,000 | 9,760 | −2.4
July 21, 2011 | September 7–8, 2011 | 25,000 | 28,800 | 15.2
July 21, 2011 | September 7–8, 2011 | 50,000 | 51,600 | 3.3

2H4MBP = 2-hydroxy-4-methoxybenzophenone.

^a^ Average of triplicate analysis.

Table A-4 Results of Analyses of Dose Formulations Administered to Rats in the Modified One-Generation Study of 2-Hydroxy-4-methoxybenzophenone

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
2H4MBP
February 6, 2012 | February 8–9, 2012 | 3,000 | 2,960 | −1.3
February 6, 2012 | February 8–9, 2012 | 10,000 | 10,000 | 0.0
February 6, 2012 | February 8–9, 2012 | 30,000 | 30,100 | 0.3
April 16, 2012 | April 20–21, 2012^b^ | 3,000 | 3,075 | 2.5
April 16, 2012 | April 20–21, 2012^b^ | 10,000 | 10,225 | 2.3
April 16, 2012 | April 20–21, 2012^b^ | 30,000 | 30,300 | 1.0
July 2, 2012 | July 10–11, 2012^b^ | 3,000 | 3,020 | 0.7
July 2, 2012 | July 10–11, 2012^b^ | 10,000 | 10,185 | 1.9
July 2, 2012 | July 10–11, 2012^b^ | 30,000 | 31,583 | 5.3
Animal Room Samples
February 6, 2012 | March 22–23, 2012 | 3,000 | 2,990 | −0.3
February 6, 2012 | March 22–23, 2012 | 10,000 | 9,600 | −4.0
February 6, 2012 | March 22–23, 2012 | 30,000 | 31,300 | 4.3
EE
February 3, 2012 | February 10, 2012, and February 19, 2012 | 0.05 | 0.0503 | 0.6
April 13, 2012 | April 20–21, 2012 | 0.05 | 0.0488 | −2.4
April 13, 2012 | April 20–21, 2012 | 0.05^c^ | 0.0449 | −11.0
April 30, 2012 | May 11–12, 2012 | 0.05^c^ | 0.0563 | 12.6
June 28, 2012 | July 11–12, 2012 | 0.05 | 0.0448 | −10.4
June 28, 2012 | July 11–12, 2012 | 0.05 | 0.0524 | 4.8

2H4MBP = 2-hydroxy-4-methoxybenzophenone; EE = ethinyl estradiol.

^a^ Average of triplicate analysis.

^b^ Average of two samples with triplicate analysis per sample.

^c^ Not used due to an unacceptable concentration.

Figure A-1

Reference (Top) and Sample (Bottom) Infrared Absorption Spectra for 2-Hydroxy-4-methoxybenzophenone

Figure A-2

Reference (Top) and Sample (Bottom) Infrared Absorption Spectra for Ethinyl Estradiol