# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2690-2052

DOI: https://doi.org/10.22427/NTP-DART-04

Report Series: NTP Developmental and Reproductive Toxicity Report Series

Report Series Number: 04

Official citation: National Toxicology Program (NTP). 2020. NTP developmental and reproductive toxicity technical report on the prenatal developmental studies of dimethylaminoethanol bitartrate (CASRN 5988-51-2) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (gavage studies). Research Triangle Park, NC: National Toxicology Program. DART Report 04.