# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  K.A. Shipkowski, Ph.D., Co-study Scientist
  V.L. Sutherland, Ph.D., Co-study Scientist
  C.R. Blystone, Ph.D.
  H.C. Cunny, Ph.D.
  J.M. Fostel, Ph.D.
  P.M. Foster, Ph.D. (Retired)
  V. Robinson, M.A.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D. (Retired)
  B.S. McIntyre, Ph.D.
  K.R. Ryan, Ph.D.
  K.R. Shockley, Ph.D.
  M.K. Vallant, M.S., MT (Retired)
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  A.T.D. Watson, Ph.D.
- Southern Research, Birmingham, Alabama, USA
  Conducted studies and evaluated findings
  C.D. Hébert, Ph.D., Principal Investigator
  E. Mylchreest, Ph.D., Study Director
  A.H. Stokes, Ph.D., Study Director
- Social & Scientific Systems, Inc., Research Triangle Park, North Carolina, USA
  Provided statistical analyses
  M.V. Smith, Ph.D., Principal Investigator
  L.J. Betz, M.S.
  S.F. Harris, B.S.
  J.D. Krause, Ph.D.
  C.G. Leach, M.S.
- RTI International, Research Triangle Park, North Carolina, USA
  Conducted pre-test chemistry activities and dose formulations
  R.A. Fernando, Ph.D.
  S.D. Cooper, B.S.
  J. Blake, B.S.