# References

1 The Merck index. 14th ed. Whitehouse Station (NJ): Merck and Company, Inc; 2006. p. 480.
2 Sigma Aldrich. Safety data sheet: 2-dimethylaminoethanol (+)-bitartrate salt. 2014. http://www.sigmaaldrich.com [Accessed: December 1, 2016]
3 Hazardous Substances Data Bank (HSDB). 2-Dimethylaminoethanol. CASRN: 108-01-0. Bethesda, MD: National Library of Medicine; 2015. HSDB No. 1329. https://toxnet.nlm.nih.gov/cgi-bin/sis/search/a?dbs+hsdb:@term+@DOCNO+1329 [Profile updated: October 19, 2015]
4 U.S. Environmental Protection Agency (USEPA). Toxic Substances Control Act (TSCA) Inventory Update Rule (IUR). 2016. https://www.epa.gov/chemical-data-reporting/2016-chemical-data-reporting-results [Accessed: January 16, 2018]
5 Organisation for Economic Co-operation and Development (OECD) The 2004 OECD list of high production volume chemicals. Paris, France: OECD Environment Directorate, Environment, Health and Safety Division; 2004.
6 U.S. Environmental Protection Agency (USEPA). Chemical Data Reporting (CDR) database. 2011. https://chemview.epa.gov/chemview [Accessed: January 16, 2018]
7 Organisation for Economic Co-operation and Development (OECD). Screening information data set: N,N-Dimethylamino-2-ethanol. Processed by International Register of Potentially Toxic Chemicals. New York, NY and Geneva, Switzerland: A contribution to the United Nations, International Programme on Chemical Safety; 1996.
8 Pitts JN Jr, Winer AM, Carter WPL. Chemical consequences of air quality standards and of control implementation programs. Riverside, CA: University of California, Statewide Air Pollution Research Center; 1981. Report No. ARB-R-80/131, NTIS Order No. PB81-137697.
9 National Toxicology Report (NTP). Dimethylethanolamine (DMAE) [108-01-0] and selected salts and esters. Review of toxicological literature (update). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2002. https://ntp.niehs.nih.gov/ntp/htdocs/chem_background/exsumpdf/dmae_update_110002_508.pdf [Accessed: June 22, 2017]
10 De Silva L Biochemical mechanisms and management of choreiform movement disorders. Drugs. 1977;14(4):300–310. 10.2165/00003495-197714040-00005 144049
11 Rothe J Cordelair H Wehman C New catalysts for low VOC in flexible slabstock foam. J Cell Plast. 2001;37(3):207–220.10.1106/X6BV-73PB-6FQC-KCRN
12 Stenbäck F Weisburger JH Williams GM Effect of lifetime, administration of dimethylaminoethanol on longevity, aging changes, and cryptogenic neoplasms in C3H mice. Mech Ageing Dev. 1988;42(2):129–138. 10.1016/0047-6374(88)90068-1 3361965
13 Hendler SS Rorvik Deditors. PDR for Nutritional Supplements. Montvale (NJ): Thomson Healthcare; 2001. Deanol; p. 123–124.
14 Source Naturals®. Dimethylaminoethanol bitartrate (DMAE). 2017. https://www.sourcenaturals.com/products/GP1101 [Accessed: June 22, 2017]
15 Nature’s Plus. Pedi-active (phosphatidylserion, DMAE complex). 2017. https://naturesplus.com/products/productdetail.php?productNumber=3000 [Accessed: June 22, 2017]
16 Source Naturals®. Attentive Child (TM). 2017. https://www.sourcenaturals.com/products/GP1028 [Accessed: June 22, 2017]
17 Dormard Y Levron JC Benakis A Pharmacokinetic study of maleate acid of 2-(N, N-dimethylaminoethanol-14C1)-cyclohexylpropionate (cyprodenate) and of N, N-dimethylaminoethanol-14C1 in animals. Arzneimittelforschung. 1975;25(2):194–201. 1173032
18 Zahniser N Chou D Hanin I Is 2-dimethylaminoethanol (deanol) indeed a precursor of brain acetylcholine? A gas chromatographic evaluation. J Pharmacol Exp Ther. 1977;200(3):545–559. 850128
19 Ceder G Schuberth J 2‐Dimethylaminoethanol (deaner) in body fluids. J Pharm Pharmacol. 1977;29(1):373–374. 10.1111/j.2042-7158.1977.tb11341.x 18579
20 Shipkowski KA Sanders JM McDonald JD Garner CE Doyle-Eisele M Wegerski CJ Waidyanatha S Comparative disposition of dimethylaminoethanol and choline in rats and mice following oral or intravenous administration. Toxicol Appl Pharmacol. 2019;378:114592. 10.1016/j.taap.2019.05.011 31100288
21 Schlenk DK Dimethylaminoethanol. In: Buhler DR Reed DJeditors. Ethel Browning’s Toxicity and Metabolism of Industrial Solvents. 2nd ed. New York (NY): Elsevier Science Publishers; 1990. p. 417–422.
22 Miyazaki H Nambu K Minaki Y Hashimoto M Nakamura K Comparative studies on the metabolism of β-dimethylaminoethanol in the mouse brain and liver following administration of β-dimethyl-aminoethanol and its p-chlorophenoxyacetate, meclofenoxate. Chem Pharm Bull (Tokyo). 1976;24(4):763–769. 10.1248/cpb.24.763 779989
23 Jope RS Jenden DJ Dimethylaminoethanol (deanol) metabolism in rat brain and its effect on acetylcholine synthesis. J Pharmacol Exp Ther. 1979;211(3):472–479. 512912
24 Beard RR Noe JT Aliphatic and alicyclic amines. In: Clayton GD Clayton FEeditors. Patty’s Industrial Hygiene and Toxicology. 3rd ed. New York (NY): John Wiley & Sons, Inc; 1981. p. 3135–3173.
25 Fisher MC Zeisel SH Mar MH Sadler TW Inhibitors of choline uptake and metabolism cause developmental abnormalities in neurulating mouse embryos. Teratology. 2001;64(2):114–122. 10.1002/tera.1053 11460263
26 Fisher MC Zeisel SH Mar M-H Sadler TW Perturbations in choline metabolism cause neural tube defects in mouse embryos in vitro. FASEB J. 2002;16(6):619–621. 10.1096/fj.01-0564fje 11919173
27 Zahniser NR Katyal SL Shih TM Hanin I Moossy J Martinez AJ Lombardi B Effects of N-methylaminoethanol, and N,N-dimethylaminoethanol in the diet of pregnant rats on neonatal rat brain cholinergic and phospholipid profile. J Neurochem. 1978;30(6):1245–1252. 10.1111/j.1471-4159.1978.tb10452.x 670968
28 Leung HW Tyl RW Ballantyne B Klonne DR Developmental toxicity study in Fischer 344 rats by whole‐body exposure to N, N‐dimethylethanolamine vapor. J Appl Toxicol. 1996;16(6):533–538. 10.1002/(SICI)1099-1263(199611)16:6<533::AID-JAT391>3.0.CO;2-B 8956100
29 Tyl RW Homan ER Klonne DR Pritts IM Fowler EH Fisher LC France KA Rebick TA Beskitt JL Ballantyne B Developmental toxicity evaluation of inhaled N,N-dimethylethanolamine (DMEA) in Fischer 344 rats. Toxicologist. 1987;7:173.
30 Shaw GM Carmichael SL Yang W Selvin S Schaffer DM Periconceptional dietary intake of choline and betaine and neural tube defects in offspring. Am J Epidemiol. 2004;160(2):102–109. 10.1093/aje/kwh187 15234930
31 Shaw GM, Finnell RH, Blom HJ, Carmichael SL, Vollset SE, Yang W, Ueland PM. Choline and risk of neural tube defects in a folate-fortified population. Epidemiology. 2009:714-719. 10.1097/EDE.0b013e3181ac9fe7
32 Mills JL Fan R Brody LC Liu A Ueland PM Wang Y Kirke PN Shane B Molloy AM Maternal choline concentrations during pregnancy and choline-related genetic variants as risk factors for neural tube defects. Am J Clin Nutr. 2014;100(4):1069–1074. 10.3945/ajcn.113.079319 25240073
33 Hartung R Cornish HH Cholinesterase inhibition in the acute toxicity of alkyl-substituted 2-aminoethanols. Toxicol Appl Pharmacol. 1968;12(3):486–494.10.1016/0041-008X(68)90155-5
34 Union Carbide. Initial submission: N,N-dimethylethanolamine: Acute toxicity and primary irritancy studies (project report) with cover sheet and letter dated 05/05/92. U.S. Environmental Protection Agency (USEPA), Toxic Substances Control Act (TSCA) Section 8ECP Test Submission; 1986. Doc. No. 88-920002183. Fiche No. OTS0536318.
35 Klonne DR Dodd DE Pritts IM Nachreiner DJ Fowler EH Troup CM Homan ER Ballantyne B Dimethylethanolamine: Acute, 2-week, and 13-week inhalation toxicity studies in rats. Fundam Appl Toxicol. 1987;9(3):512–521. 10.1016/0272-0590(87)90033-9 3692010
36 Murray MP Cummins JE Mutagenic activity of epoxy embedding reagents employed in electron microscopy. Environ Mutagen. 1979;1(4):307–313. 10.1002/em.2860010402 399914
37 Union Carbide. Dimethylethanolamine (DMEA). Salmonella/microsomes (Ames) bacterial mutagenicity assay. Westmoreland, PA: Bushy Run Research Center; 1987. Project Report 50-85.
38 Union Carbide. Dimethylethanolamine (DMEA). In vitro genotoxicity studies: CHO/HGPRT gene mutation test and sister chromatid exchange assay. Westmoreland, PA: Bushy Run Research Center; 1988. Project Report 50-130.
39 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K, Speck W. Salmonella mutagenicity tests: III. Results from the testing of 255 chemicals. Environ Mutagen. 1987; 9(S9 S9):61-109.
40 Leung H-W Ballantyne B Evaluation of the genotoxic potential of alkylalkanolamines. Mutat Res Genet Toxicol Environ Mutagen. 1997;393(1-2):7–15. 10.1016/S1383-5718(97)00104-6 9357557
41 Gosselin RE Smith RP Hodge HCeditors. Clinical Toxicology of Commercial Products. 5th ed. Baltimore (MD): Wilkens and Wilkens Company; 1984. Ingredients index: Deanol; p. 240.
42 Mehta D Mehta S Mathew P Failure of deanol in treating tardive dyskinesia. Am J Psychiatry. 1976;133(12):1467–1467. 10.1176/ajp.133.12.1467a 984253
43 Nesse RM Carroll BJ Cholinergic side-effects associated with deanol. Lancet. 1976;2:50–51. 10.1016/S0140-6736(76)93016-6 59121
44 Soares KVS McGrath JJ The treatment of tardive dyskinesia: A systematic review and meta-analysis. Schizophr Res. 1999;39(1):1–16. 10.1016/S0920-9964(99)00021-3 10480663
45 Tammenmaa I McGrath J Sailas EES Soares‐Weiser K Cholinergic medication for neuroleptic‐induced tardive dyskinesia. Cochrane Database Syst Rev. 2002;3:1–33. 12137608
46 Chernoff N Setzer RW Miller DB Rosen MB Rogers JM Effects of chemically induced maternal toxicity on prenatal development in the rat. Teratology. 1990;42(6):651–658. 10.1002/tera.1420420610 2087686
47 U.S. Environmental Protection Agency (USEPA). Guidelines for developmental toxicity risk assessment. Washington, DC: U.S. Environmental Protection Agency, Risk Assessment Forum; 1991. EPA Document No. EPA/600/FR-91/001.
48 Tyl RW Commentary on the role of maternal toxicity on developmental toxicity. Birth Defects Res B Dev Reprod Toxicol. 2012;95(3):262–266. 10.1002/bdrb.21015 22706915
49 Organisation for Economic Co-operation and Development (OECD). OECD guideline for the testing of chemicals: Prenatal developmental toxicity study. Paris, France: Organisation for Economic Cooperation and Development; 2001., OECD 414.
50 Makris SL Solomon HM Clark R Shiota K Barbellion S Buschmann J Ema M Fujiwara M Grote K Hazelden KP Terminology of developmental abnormalities in common laboratory mammals (version 2). Congenit Anom (Kyoto). 2009;49(3):123–246. 10.1111/j.1741-4520.2009.00239.x 20002907
51 National Institute of Standards and Technology (NIST). Mass spectral library: Wiley Registry, 8th ed. Revision D06.00, version G1035B, entry 78256. New York, NY: Wiley and Sons, Inc; 2005.
52 National Toxicology Program (NTP). DART-04: Growth and clinical finding tables (I), pathology tables (PA), developmental and reproductive tables (R) from NTP developmental and reproductive toxicity studies. Research Triangle Park, NC. 2019. 10.22427/NTP-DATA-DART-04
53 Suckow MA Weisbroth SH Franklin CL The laboratory rat. 2nd ed. Amsterdam, Netherlands: Elsevier; 2006.
54 Hayes AW Kruger CL Hayes’ principles and methods of toxicology. 6th ed. New York (NY): CRC Press; 2014. p. 1670–1674. 10.1201/b17359
55 Salewski E Färbemethode zum makroskopischen nachweis von implantationsstellen am uterus der ratte. Naunyn Schmiedebergs Arch Pharmacol. 1964;247(4):367.10.1007/BF02308461
56 Tyl RW Marr MC Developmental toxicity texting – methodology. Developmental and Reproductive Toxicology. 2nd ed. New York (NY): Taylor and Francis Group; 2006. p. 201–261.
57 Staples RE Detection of visceral alterations in mammalian fetuses. Teratology. 1974;9:A37–A38.
58 Stuckhardt JL Poppe SM Fresh visceral examination of rat and rabbit fetuses used in teratogenicity testing. Teratog Carcinog Mutagen. 1984;4(2):181–188. 10.1002/tcm.1770040203 6145223
59 Thompson RF Basic neuroanatomy. Foundations of Physiological Psychology. New York (NY): Harper and Row Publishers; 1967. p. 79–82.
60 Marr MC Price CJ Myers CB Morrissey RE Developmental stages of the CD®(Sprague‐Dawley) rat skeleton after maternal exposure to ethylene glycol. Teratology. 1992;46(2):169–181. 10.1002/tera.1420460210 1440420
61 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121.10.1080/01621459.1955.10501294
62 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27:103–117. 10.2307/2528930 5547548
63 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28:519–531. 10.2307/2556164 5037867
64 Shirley E. A non-parametric equivalent of Williams' test for contrasting increasing dose levels of a treatment. Biometrics. 1977:386-389. 10.2307/2529789
65 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42:183–186. 10.2307/2531254 3719054
66 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252.10.1080/00401706.1964.10490181
67 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1/2):133–145.10.2307/2333011
68 Dixon WJ Massey FJ Jr Introduction to statistical analysis. 2nd ed. New York (NY): McGraw-Hill Book Company, Inc; 1957. p. 276–278, 412.
69 Hsu JC The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992;1(2):151–168.
70 Armitage P Tests for linear trends in proportions and frequencies. Biometrics. 1955;11(3):375–386.10.2307/3001775
71 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
72 Zorrilla EP Multiparous species present problems (and possibilities) to developmentalists. Dev Psychobiol. 1997;30(2):141–150. 10.1002/(SICI)1098-2302(199703)30:2<141::AID-DEV5>3.0.CO;2-Q 9068968
73 Pendergast JF Gange SJ Lindstrom MJ Encyclopedia of Biostatistics. Hoboken (NJ): John Wiley & Sons, Ltd; 2005. Correlated binary data. 10.1002/0470011815.b2a10018
74 Li B Lingsma HF Steyerberg EW Lesaffre E Logistic random effects regression models: A comparison of statistical packages for binary and ordinal outcomes. BMC Med Res Methodol. 2011;11:77. 10.1186/1471-2288-11-77 21605357
75 Scott WJ Jr Resnick E Hummler H Clozel J-P Bürgin H Cardiovascular alterations in rat fetuses exposed to calcium channel blockers. Reprod Toxicol. 1997;11(2-3):207–214. 10.1016/S0890-6238(97)00008-7 9100294
76 Huntsman Corporation Technical bulletin: N,N-dimethylethanolamine. Houston (TX): DMEA; 2007.
77 Wickramaratne GA The post‐natal fate of supernumerary ribs in rat teratogenicity studies. J Appl Toxicol. 1988;8(2):91–94. 10.1002/jat.2550080205 3379236
78 Foulon O Jaussely C Repetto M Urtizberea M Blacker AM Postnatal evolution of supernumerary ribs in rats after a single administration of sodium salicylate. J Appl Toxicol. 2000;20(3):205–209. 10.1002/(SICI)1099-1263(200005/06)20:3<205::AID-JAT635>3.0.CO;2-G 10797473
79 Chernoff N Rogers JM Supernumerary ribs in developmental toxicity bioassays and in human populations: incidence and biological significance. J Toxicol Environ Health. 2004;7(6):437–449. 10.1080/10937400490512447 15586878
80 Bellary SS Steinberg A Mirzayan N Shirak M Tubbs RS Cohen‐Gadol AA Loukas M Wormian bones: A review. Clin Anat. 2013;26(8):922–927. 10.1002/ca.22262 23959948
81 Lefebvre V Bhattaram P Vertebrate skeletogenesis. Curr Top Dev Biol. 2010;90:291–317. 10.1016/S0070-2153(10)90008-2 20691853
82 Clares B Ruiz MA Morales ME Tamayo JA Lara VG Structural characterization and stability of dimethylaminoethanol and dimethylaminoethanol bitartrate for possible use in cosmetic firming. J Cosmet Sci. 2010;61(4):269–278. 10.1111/j.1468-2494.2010.00620_1.x 20716435
83 SDBSweb. SDBS No. 3992. 2019. http://sdbs.riodb.aist.go.jp/sdbs/cgi-bin/direct-frametop.cgi?lang=eng [Accessed: January 18, 2019]
84 U.S. Environmental Protection Agency (USEPA). Dimethylaminoethanol. USEPA Chemistry Dashboard. 2018. https://comptox.epa.gov/dashboard/dsstoxdb/results?search=dimethylaminoethanol#properties [Accessed: October 1, 2018]