# Conclusions

Under the conditions of this prenatal study, there was equivocal evidence of developmental toxicity of dimethylaminoethanol bitartrate in Hsd:Sprague Dawley^®^ SD^®^ rats attributable to increased incidences of absent innominate artery, short thoracolumbar ribs, and supernumerary sites in the skull in the absence of overt maternal toxicity.