# Discussion

Dimethylaminoethanol is a close structural analog of choline (N,N,N-trimethylaminoethanol), an essential nutrient. Dimethylaminoethanol supplies the brain with choline, where it is acetylated to form acetylcholine.^10^ Choline is required for many biological processes, including nervous system development, and choline deficiency has been associated with neural tube defects (NTDs) in both rodents and humans.^25;^ ^26;^ ^30-32^ Human exposure to dimethylaminoethanol can occur in occupational settings (e.g., spray painting, beverage can lacquering);^8^ however, the primary exposure pathway in the U.S. population is consumption of dimethylaminoethanol as a dietary supplement. Dietary supplements containing dimethylaminoethanol bitartrate, a salt of dimethylaminoethanol, are marketed to improve memory and general cognitive function due to the ability of ingested dimethylaminoethanol to increase levels of acetylcholine in the brain. Dimethylaminoethanol bitartrate supplements are also purported to treat symptoms of attention deficit hyperactivity disorder (ADHD) in children.

There are indications in the literature on experiments in rodents that exposure to dimethylaminoethanol can induce developmental and reproductive toxicity, including decreases in viable implants, litter size, and pup survival and increases in fetal skeletal variations.^27-29^ Due to the potential for widespread human exposure and concerns for use by pregnant women and children, the NTP conducted prenatal developmental toxicity studies in rats to assess the effects of oral dimethylaminoethanol bitartrate administration on pregnant females and on fetal development.

There were no indications of maternal or fetal toxicity in the dose range-finding study following exposure to 0, 250, 500, or 1,000 mg/kg/day dimethylaminoethanol bitartrate. As no maternal toxicity was observed in the dose range-finding study, identical doses of 250, 500, and 1,000 mg/kg/day dimethylaminoethanol bitartrate were chosen for the prenatal developmental toxicity study. Dimethylaminoethanol bitartrate was well tolerated in the prenatal developmental toxicity study, allowing for a complete evaluation of embryo-fetal development following exposure. There were no significant effects on maternal survival, body weight, or food consumption. One dam in the 1,000 mg/kg group was euthanized moribund (GD 21), and one other was found dead (GD 10, gavage accident), but these deaths were not considered dose-related. Marginal increases in liver weights were observed, and similar results have been reported in the literature with dimethylaminoethanol (45 to 890 mg/kg) in the diet for 90 days causing increased liver weights with no associated histopathologic changes.^76^ The marginal increases in liver weight observed in this study were not considered to be toxicologically significant.

Exposure to dimethylaminoethanol bitartrate did not affect any pregnancy or litter parameters. The dam administered 1,000 mg/kg dimethylaminoethanol bitartrate and euthanized moribund on GD 21 had 11 dead fetuses and one early resorption. Including the data for that one female resulted in a higher calculated postimplantation loss that was unlikely to be exposure related or representative of the entire dose group. Fetal body weight, a sensitive indicator of embryo-fetal toxicity, was unaffected in all exposure groups in the dose range-finding and prenatal developmental toxicity studies.

There were minimal significant findings of increased incidences of variations in fetal morphology, which included absent innominate artery, short thoracolumbar ribs (short supernumerary ribs), and supernumerary sites in the skull. Absent innominate artery was noted in some fetuses in all groups, including the control group, but occurred at a slightly higher incidence, 4.6% of fetuses and 45.5% of litters, in dams administered dimethylaminoethanol bitartrate at 1,000 mg/kg/day. Those incidences were considered potentially exposure related, because the percentage of affected fetuses and litters were outside the NTP historical control ranges (1.37–2.82% fetuses; 15.8–27.8% litters). Innominate artery variations have been reported in the literature, however, in approximately 5% of control rat fetuses.^75^ Short supernumerary ribs occurred in 86–90% of litters across all groups, but the fetal incidence was significantly higher, by 12%, in the 1,000 mg/kg fetuses (38.5%) relative to the vehicle control group (26.8%). This increase was considered exposure related, because the percentage of affected fetuses was outside the NTP historical control range (9.90–26.79% for fetuses); however, this did not correspond to an increase in full thoracolumbar ribs (a malformation), and this is also a common background variation in the Sprague Dawley rat strain used in this study. The manifestation of short supernumerary ribs is short-lived, as this particular variation is considered reversible during postnatal development.^77-79^ The incidence of supernumerary sites in the skull was significantly increased in 1,000 mg/kg fetuses (approximately 10%) relative to the vehicle control group (1%) and outside of the NTP historical control range (0.70–2.94% for fetuses). This increase, therefore, was considered to be treatment-related; however, the toxicological significance of this finding is unclear. There are minimal available animal data evaluating whether these supernumerary sites cause biological consequences later in life or resolve. In clinical research, these findings are commonly used as diagnostic markers suggestive of certain syndromes and genetic disorders such as craniosynostosis and osteogenesis imperfecta.^80^

When examined individually, the noted effects are likely common variations (absent innominate artery), reversible (supernumerary ribs), or of uncertain biological significance (supernumerary sites in the skull). However, the increased incidence of a cardiovascular finding and extra ossification sites in two separate locations could be considered an indication of altered development in exposed fetuses, particularly because the incidences are outside of the NTP historical control range and occurred in the absence of decreased fetal weight and maternal toxicity. Skull and rib development occur via two different skeletal developmental pathways, endochondral ossification (ribs) and intramembranous ossification (skull).^81^ During endochondral ossification, a cartilage template is gradually replaced with bone via osteoblasts that secrete extracellular bone matrix which undergoes mineralization to form bone. Subsequent growth requires remodeling by bone-resorbing osteoclasts followed by deposition of new bone matrix by osteoblasts. Intramembranous ossification, on the other hand, occurs in the absence of cartilage template and involves condensation of mesenchymal stem cells (osteoblast precursors) at sites of future skull bones. These precursor cells differentiate to become osteoblasts which secrete extracellular bone matrix that undergoes mineralization to form ossified bone. Both pathways require functioning osteoblasts and osteoclasts. Although differential gene expression patterns are required for each of these developmental pathways, there are genes common to both pathways (i.e., Runx2).^81^ The data in this Developmental and Reproductive Toxicity Technical Report suggest that dimethylaminoethanol bitartrate exposure might affect multiple skeletal development pathways; however, the observed rib and skull findings are of unclear biological significance.