# Results

## Data Availability

NTP evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://dx.doi.org/10.22427/NTP-DATA-DART-04.^52^

## Dose Range-finding Study in Rats

### Maternal Findings

#### Viability and Clinical Observations

All dams survived to end of the study (Table 2). There were no treatment-related clinical observations (Appendix D).

Table 2 Maternal Disposition of Rats in the Dose Range-finding Gavage Study of Dimethylaminoethanol Bitartrate

| 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Time-mated Females | 10 | 10 | 10 | 10
Pregnant Females Examined (on GD 21) | 9 | 7 | 10 | 8
Nonpregnant (on GD 21) | 1 | 3 | 0 | 2

GD = gestation day.

#### Body Weights and Feed Consumption

There were no dose-related effects on maternal body weight gain during gestation (Figure 3, Table 3; (Appendix D). One 1,000 mg/kg dam lost body weight between gestation day (GD) 15 and GD 18 (loss of 15.5 g) and between GD 18 and GD 21 (loss of 23.7 g), which coincided with decreased feed consumption by the same animal. This body weight decrease was not considered treatment related.

Figure 3

Maternal Growth Curves for Pregnant Rats Administered Dimethylaminoethanol Bitartrate by Gavage in the Dose Range-finding Study

Information for statistical significance in maternal weights is provided in Table 3 and (Appendix D

Table 3 Summary of Maternal Body Weight Gains of Rats in the Dose Range-finding Gavage Study of Dimethylaminoethanol Bitartrate^a^

Gestation Day Interval | 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
6–21 | 121.5 ± 10.5 (9) | 124.4 ± 12.9 (7) | 137.5 ± 5.5 (10) | 119.0 ± 15.9 (8)
3–6 | 15.7 ± 2.7 (9) | 15.1 ± 1.1 (7) | 14.8 ± 1.0 (10) | 16.5 ± 1.8 (8)
6–9 | 13.9 ± 1.1 (9) | 11.9 ± 1.4 (7) | 12.9 ± 1.5 (10) | 10.9 ± 1.0 (8)
9–12 | 14.9 ± 1.2 (9) | 15.0 ± 0.9 (7) | 16.1 ± 1.1 (10) | 15.9 ± 0.6 (8)
12–15 | 18.0 ± 2.0 (9) | 19.3 ± 2.3 (7) | 19.0 ± 1.7 (10) | 18.1 ± 1.5 (8)
15–18 | 31.5 ± 2.8 (9) | 30.4 ± 4.1 (7) | 37.3 ± 2.6 (10) | 31.9 ± 7.0 (8)
18–21 | 43.3 ± 5.1 (9) | 47.8 ± 5.6 (7) | 52.3 ± 1.6 (10) | 42.2 ± 9.7 (8)

Statistical analyses performed by the Jonckheere test (trend) and the Williams or Dunnett test (pairwise comparison) found no statistically significant trend or difference from the control group in a pairwise comparison.

^a^ Body weight gains for pregnant animals are given in grams. Data are displayed as mean ± standard error (n).

Mean feed consumption for the intervals or the overall dosing period was not affected by administration of dimethylaminoethanol bitartrate (Table 4).

Table 4 Summary of Maternal Feed Consumption of Rats in the Dose Range-finding Gavage Study of Dimethylaminoethanol Bitartrate^a^

Gestation Day Interval | 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
6–21 | 21.8 ± 0.4 (9) | 22.0 ± 0.7 (7) | 22.3 ± 0.6 (10) | 21.7 ± 0.8 (8)
6–9^b^ | 19.3 ± 0.2 (4) | 19.3 ± 0.9 (3) | 18.9 ± 1.1 (5) | 19.1 ± 0.3 (4)
9–12 | 21.6 ± 0.5 (9) | 21.2 ± 0.8 (7) | 22.0 ± 0.5 (10) | 21.9 ± 0.7 (8)
12–15 | 21.6 ± 0.4 (9) | 21.6 ± 0.9 (7) | 21.2 ± 0.6 (10) | 21.3 ± 0.3 (8)
15–18 | 23.4 ± 0.5 (9) | 23.2 ± 0.8 (7) | 24.3 ± 0.8 (10) | 24.0 ± 1.0 (8)
18–21 | 23.6 ± 0.7 (9) | 24.6 ± 1.0 (7) | 24.6 ± 0.5 (10) | 22.2 ± 3.0 (8)

Statistical analysis performed by the Jonckheere test (trend) and the Shirley or Dunn test (pairwise comparison) found no statistically significant trend or pairwise comparison to the control group.

^a^ Feed consumption for pregnant animals in grams/day. Data are displayed as mean ± standard error. Number of dams with feed consumption measured is given in parentheses.

^b^ Because of a technical error, feed consumption was not recorded for a number of dams on GD 9.

#### Maternal and Litter Observations

Gross observations at necropsy were limited to skin discoloration in one 1,000 mg/kg rat and fluid in the uterus of one 250 mg/kg rat and one 1,000 mg/kg rat (Appendix D). These observations were not considered related to chemical administration.

The number of pregnant animals, the mean number of corpora lutea, dead fetuses, early and late resorptions, and sex ratio were similar across all treatment groups (Table 5). There was a significant positive trend in the mean number of live female fetuses per litter relative to dose (Table 5). There was no effect of dose on mean fetal body weight per litter.

Table 5 Summary of Maternal Feed Consumption of Rats in the Dose Range-finding Gavage Study of Dimethylaminoethanol Bitartrate^a^

| 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Pregnancy Summary
Mated females | 10 | 10 | 10 | 10
Pregnant females | 9 | 7 | 10 | 8
Pregnant females examined on GD 21^a^ | 9 | 7 | 10 | 8
Corpora lutea per female^b^ | 14.89 ± 0.54 (9) | 16.00 ± 1.23 (7) | 15.40 ± 0.65 (10) | 14.75 ± 0.65 (8)
Implantations per female^b^ | 11.33 ± 1.38 (9) | 11.86 ± 1.90 (7) | 13.10 ± 0.71 (10) | 14.00 ± 0.65 (8)
Percent postimplantation loss^b^ | 10.22 ± 7.35 (9) | 0.95 ± 0.95 (7) | 2.30 ± 1.19 (10) | 3.42 ± 1.30 (8)
Total resorptions per litter^b^ | 0.56 ± 0.29 (9) | 0.14 ± 0.14 (7) | 0.30 ± 0.15 (10) | 0.50 ± 0.19 (8)
Early resorptions per litter^b^ | 0.56 ± 0.29 (9) | 0.14 ± 0.14 (7) | 0.30 ± 0.15 (10) | 0.50 ± 0.19 (8)
Late resorptions per litter^b^ | 0.00 ± 0.00 (9) | 0.00 ± 0.00 (7) | 0.00 ± 0.00 (10) | 0.00 ± 0.00 (8)
Dead fetuses per litter^b^ | 0.00 ± 0.00 (9) | 0.00 ± 0.00 (7) | 0.00 ± 0.00 (10) | 0.00 ± 0.00 (8)
Number of early resorptions^c^ | 5 | 1 | 3 | 4
Number of late resorptions | 0 | 0 | 0 | 0
Number of whole litter resorptions | 0 | 0 | 0 | 0
Number of dead fetuses | 0 | 0 | 0 | 0
Live Fetuses^b^
Number of live fetuses | 97 | 82 | 128 | 108
Live fetuses per litter | 10.78 ± 1.55 (9) | 11.71 ± 1.86 (7) | 12.80 ± 0.71 (10) | 13.50 ± 0.60 (8)
Live male fetuses per litter | 5.56 ± 1.09 (9) | 7.00 ± 1.31 (7) | 7.10 ± 0.80 (10) | 6.38 ± 0.65 (8)
Live female fetuses per litter | 5.22 ± 0.88 (9)* | 4.71 ± 1.02 (7) | 5.70 ± 0.83 (10) | 7.13 ± 0.30 (8)
Percent live male fetuses per litter | 44.84 ± 8.15 (9) | 64.57 ± 8.10 (7) | 55.99 ± 5.40 (10) | 46.54 ± 2.99 (8)
Fetal Weight (g)^d^
Fetal body weight per litter | 5.39 ± 0.05 (9) | 5.39 ± 0.17 (7) | 5.40 ± 0.05 (10) | 5.08 ± 0.40 (8)
Male fetal weight per litter | 5.53 ± 0.07 (8) | 5.45 ± 0.16 (7) | 5.52 ± 0.06 (10) | 5.21 ± 0.41 (8)
Female fetal weight per litter | 5.26 ± 0.09 (9) | 5.18 ± 0.15 (6) | 5.25 ± 0.05 (10) | 4.97 ± 0.39 (8)
Gravid Uterine Weight (g)^e^
Gravid uterine weight | 80.57 ± 10.81 (9) | 84.13 ± 14.08 (7) | 94.56 ± 4.66 (10) | 93.54 ± 5.54 (8)
Terminal body weight | 363.1 ± 12.0 (9) | 360.8 ± 12.9 (7) | 377.8 ± 7.3 (10) | 361.3 ± 16.0 (8)
Adjusted body weight | 282.56 ± 4.18 (9) | 276.63 ± 5.67 (7) | 283.24 ± 4.73 (10) | 267.80 ± 11.29 (8)

Values are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to the end of the study.

* Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column).

GD = gestation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

^b^ Statistical analysis of number per litter or female performed by the Jonckheere’s (trend) and Shirley or Dunn (pairwise) tests.

cStatistical analysis not performed on number of early resorptions.

^d^ Statistical analysis performed using a mixed-effects linear model with litter as a random effect (trend and pairwise).

^e^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests; adjusted body weight = terminal body weight minus gravid uterine weight.

### Fetal Findings

#### External

No external malformations or variations were observed in either the vehicle control or exposed groups (Appendix D).

### Dose Selection Rationale for the Prenatal Developmental Toxicity Study in Rats

No maternal toxicity was observed in the dose range-finding study up to the limit dose of 1,000 mg/kg. Thus, dose concentrations of 250, 500, and 1,000 mg/kg dimethylaminoethanol bitartrate were chosen for the subsequent prenatal developmental toxicity gavage study.

## Prenatal Developmental Toxicity Study in Rats

### Maternal Findings

#### Viability and Clinical Observations

One 1,000 mg/kg/day dam was euthanized moribund on GD 21 following observations of dehydration, coldness to touch, brown discoloration in both eyes, and hypoactivity, but it is unclear if this condition was related to treatment (Table 6). Offspring from this dam were examined and included in fetal assessments. A second 1,000 mg/kg dam was found dead on GD 10; however, this death was determined to be the result of a gavage accident given the breathing difficulties observed after dosing. One vehicle control dam and one 1,000 mg/kg dam delivered prior to scheduled C-section on GD 21, and were therefore euthanized on GD 19 and 20, respectively. All other dams survived to the end of the study.

Table 6 Maternal Disposition of Rats in the Prenatal Developmental Toxicity Gavage Study of Dimethylaminoethanol Bitartrate

| 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Time-mated Females | 25 | 25 | 25 | 25
Pregnant Females Examined (on GD 21) | 19 | 20 | 20 | 21
Delivered Early | 1^a^ | 0 | 0 | 1^b^
Euthanized Moribund | 0 | 0 | 0 | 1^c^
Found Dead | 0 | 0 | 0 | 1^d^
Nonpregnant (on GD 21) | 5 | 5 | 5 | 1

GD = gestation day.

^a^ Dam removed on GD 19.

^b^ Dam removed on GD 20.

^c^ Dam removed on GD 21; dam and offspring were included in maternal and fetal assessments.

^d^ Dam removed on GD 10.

Clinical observations were generally limited to single or sporadic incidences among groups except vaginal discharge (Appendix D). Brown or red vaginal discharge was observed between GD 14 and GD 21 in 10, 3, 4, and 10 dams in the 0, 250, 500, and 1,000 mg/kg groups, respectively; however, given the lack of a dose-response trend, the observations of vaginal discharge were considered unrelated to chemical administration.

#### Body Weights and Feed Consumption

There were no dose-related effects on maternal body weight or body weight gain during gestation in any dose group (Figure 4 and Table 7; (Appendix D); however, there was a significant increase (approximately 16%) in body weight gain in the 500 mg/kg/day dams relative to the vehicle control group between GD 6 and GD 21 (Table 7).

Figure 4

Maternal Growth Curves for Pregnant Rats Administered Dimethylaminoethanol Bitartrate by Gavage in the Prenatal Developmental Toxicity Study

Information for statistical significance in maternal weights is provided in Table 7 and (Appendix D

Table 7 Summary of Maternal Body Weight Gains of Rats in the Prenatal Developmental Toxicity Gavage Study of Dimethylaminoethanol Bitartrate^a^

Gestation Day Interval | 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
6–21 | 120.5 ± 7.5 (19) | 135.2 ± 4.7 (20) | 140.0 ± 4.2* (20) | 127.7 ± 5.8 (21)
3–6 | 11.8 ± 0.9 (20) | 11.3 ± 0.9 (20) | 11.6 ± 1.2 (20) | 11.1 ± 0.8 (24)
6–9 | 13.6 ± 0.6 (20) | 14.1 ± 1.0 (20) | 13.7 ± 0.9 (20) | 13.3 ± 1.1 (24)
9–12 | 15.2 ± 0.8 (20) | 15.0 ± 0.9 (20) | 16.4 ± 1.0 (20) | 14.8 ± 0.9 (23)
12–15 | 13.6 ± 1.9 (20) | 17.2 ± 2.3 (20) | 18.1 ± 1.3 (20) | 15.6 ± 2.1 (23)
15–18 | 37.7 ± 3.5 (20) | 41.2 ± 1.9 (20) | 42.8 ± 1.5 (20) | 35.4 ± 4.7 (23)
18–21 | 41.6 ± 3.1 (19) | 47.8 ± 2.3 (20) | 49.0 ± 2.1 (20) | 43.2 ± 2.1 (21)

Statistical analysis performed by the Jonckheere test found no statistically significant trend.

* Statistically significant (p ≤ 0.05) pairwise comparison by the Williams or Dunnett test.

^a^ Body weight gains for pregnant animals are given in grams. Data are displayed as mean ± standard error. Number of dams weighed is given in parentheses.

Mean feed consumption values were similar between vehicle control and dosed dams (Table 8). The 1,000 mg/kg pregnant dam euthanized moribund on GD 21 exhibited decreased feed consumption between GDs 15 and 21.

Table 8 Summary of Maternal Feed Consumption of Rats in the Prenatal Developmental Toxicity Study of Dimethylaminoethanol Bitartrate^a^

Gestation Day Interval | 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
6–21 | 21.2 ± 0.4 (19) | 21.6 ± 0.4 (20) | 22.0 ± 0.3 (20) | 21.5 ± 0.4 (22)
6–9 | 19.9 ± 0.3 (20) | 20.0 ± 0.3 (20) | 19.6 ± 0.4 (20) | 19.1 ± 0.5 (24)
9–12 | 20.5 ± 0.3 (20) | 20.9 ± 0.3 (20) | 20.6 ± 0.3 (20) | 20.7 ± 0.3 (23)
12–15 | 20.3 ± 0.6 (19) | 21.2 ± 0.5 (20) | 21.5 ± 0.4 (20) | 21.0 ± 0.4 (23)
15–18 | 23.1 ± 0.4* (20) | 22.7 ± 0.7 (20) | 24.5 ± 0.4 (20) | 23.7 ± 0.8 (23)
18–21 | 22.1 ± 0.5 (19) | 23.4 ± 0.6 (20) | 23.8 ± 0.5 (20) | 22.6 ± 1.1 (22)

Statistical analysis performed by the Shirley or Dunn test found no statistically different pairwise comparisons.

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test).

^a^ Feed consumption for pregnant animals in grams/day. Data are displayed as mean ± standard error. Number of dams with feed consumption measured is given in parentheses.

#### Maternal and Litter Observations

There were no dose-related gross observations noted at necropsy (Appendix D). There was a significant positive trend in mean absolute liver weight (2.5%, 3.3%, and 7.2% in the 250, 500, and 1,000 mg/kg groups respectively); however, these weights were only marginally greater than the vehicle control weight, and the relative liver weights were similar across all groups (Table 9). Therefore, this trend was not deemed treatment related. The 1,000 mg/kg pregnant dam euthanized moribund on GD 21 had the smallest recorded liver weight (8.81 g) of any animal in the study; mean absolute liver weights for all dose groups ranged from 13.96 to 14.96 g.

Table 9 Summary of Maternal Liver Weights of Rats in the Prenatal Developmental Toxicity Study of Dimethylaminoethanol Bitartrate^a^

| 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
n | 19 | 20 | 20 | 21
Terminal Body Wt. | 359.6 ± 8.8 | 375.2 ± 5.3 | 380.3 ± 5.1 | 367.1 ± 6.5
Absolute | 13.96 ± 0.37* | 14.31 ± 0.34 | 14.42 ± 0.36 | 14.96 ± 0.25
Relative | 38.91 ± 0.66 | 38.10 ± 0.64 | 37.89 ± 0.75 | 41.00 ± 1.01

Statistical analysis performed by the Williams or Dunnett tests found no statistically significant pairwise comparison.

* Significant trend (p ≤ 0.05) by the Jonckheere test.

^a^ Liver weights (absolute weights) and body weights are given in grams; liver-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight. Data are displayed as mean ± standard error.

There were no effects on pregnancy status or litter size following administration of dimethylaminoethanol bitartrate (Table 10). The mean number of corpora lutea and implantations for all dose groups were also similar to the vehicle control group. The 1,000 mg/kg pregnant dam euthanized moribund on GD 21 had 11 dead fetuses and one early resorption, which accounted for the apparent increase in percent postimplantation loss; this was not representative of the dose group. That result, therefore, was considered spurious and unrelated to treatment. There were no treatment-related effects on the number of live fetuses per litter, live male fetuses per litter, or live female fetuses per litter. Fetal body weights (male and female, or separate) were similar across all treatment groups.

Table 10 Summary of Uterine Content Data of Rats in the Prenatal Developmental Toxicity Study of Dimethylaminoethanol Bitartrate

| 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Pregnancy Summary
Mated females | 25 | 25 | 25 | 25
Pregnant females | 20 | 20 | 20 | 24
Pregnant females examined on GD 21^a^ | 19 | 20 | 20 | 22^b^
Corpora lutea per female^c^ | 15.74 ± 0.57 (19) | 15.85 ± 0.45 (20) | 16.70 ± 0.73 (20) | 15.86 ± 0.64 (22)
Implantations per female^c^ | 11.47 ± 1.11 (19) | 13.75 ± 0.54 (20) | 13.50 ± 0.60 (20) | 12.45 ± 0.87 (22)
Percent postimplantation loss^c^ | 5.05 ± 1.57 (19) | 3.80 ± 1.53 (20) | 3.45 ± 1.10 (20) | 11.17 ± 5.56 (22)
Total resorptions per litter^c^ | 0.47 ± 0.12 (19) | 0.50 ± 0.20 (20) | 0.50 ± 0.17 (20) | 0.64 ± 0.26 (22)
Early resorptions per litter^c^ | 0.47 ± 0.12 (19) | 0.50 ± 0.20 (20) | 0.50 ± 0.17 (20) | 0.64 ± 0.26 (22)
Late resorptions per litter^c^ | 0.00 ± 0.00 (19) | 0.00 ± 0.00 (20) | 0.00 ± 0.00 (20) | 0.00 ± 0.00 (22)
Dead fetuses per litter^c^ | 0.00 ± 0.00 (19) | 0.00 ± 0.00 (20) | 0.00 ± 0.00 (20) | 0.50 ± 0.50 (22)
Number of early resorptions^d^ | 9 | 10 | 10 | 14
Number of late resorptions | 0 | 0 | 0 | 0
Number of whole litter resorptions | 0 | 0 | 0 | 0
Number of dead fetuses^e^ | 0 | 0 | 0 | 11
Live Fetuses^c^
Number of live fetuses | 209 | 265 | 260 | 249
Live fetuses per litter | 11.00 ± 1.12 (19) | 13.25 ± 0.60 (20) | 13.00 ± 0.56 (20) | 11.32 ± 1.07 (22)
Live male fetuses per litter | 5.21 ± 0.68 (19) | 6.10 ± 0.55 (20) | 6.10 ± 0.55 (20) | 5.77 ± 0.67 (22)
Live female fetuses per litter | 5.79 ± 0.69 (19) | 7.15 ± 0.50 (20) | 6.90 ± 0.48 (20) | 5.55 ± 0.60 (22)
Percent live male fetuses per litter | 47.53 ± 5.21 (19) | 44.76 ± 3.98 (20) | 46.61 ± 3.23 (20) | 50.42 ± 4.39 (21)
Fetal Weight (g)^f^
Fetal body weight per litter | 5.38 ± 0.15 (19) | 5.26 ± 0.05 (20) | 5.33 ± 0.06 (20) | 5.40 ± 0.09 (21)
Male fetal weight per litter | 5.44 ± 0.16 (18) | 5.37 ± 0.05 (19) | 5.50 ± 0.06 (20) | 5.51 ± 0.09 (20)
Female fetal weight per litter | 5.15 ± 0.12 (18) | 5.14 ± 0.06 (20) | 5.18 ± 0.07 (20) | 5.21 ± 0.08 (20)
Gravid Uterine Weight (g)^g^
Gravid uterine weight | 80.18 ± 7.36 (19) | 95.85 ± 3.93 (20) | 96.17 ± 3.82 (20) | 85.25 ± 6.38 (22)
Terminal body weight | 359.6 ± 8.8 (19) | 375.2 ± 5.3 (20) | 380.3 ± 5.1 (20) | 361.4 ± 8.5 (22)
Adjusted body weight | 279.42 ± 3.68 (19) | 279.34 ± 3.77 (20) | 284.12 ± 2.90 (20) | 276.17 ± 4.59 (22)

Values are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to the end of the study. No statistically significant trends or pairwise differences from the control group were found.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

^b^ The dam euthanized moribund on GD 21 was included in the uterine content assessment.

^c^ Statistical analysis on number per female or per litter performed by the Jonckheere’s (trend) and Shirley or Dunn (pairwise) tests.

^d^ No statistical analyses performed on number of early resorptions.

^e^ One dam at 1000 mg/kg was euthanized moribund on GD 21 with 11 dead fetuses and 1 early resorption.

^f^ Statistical analysis performed using a mixed-effects linear model with litter as a random effect (trend and pairwise).

^g^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests; adjusted body weight = terminal body weight minus gravid uterine weight.

### Fetal Findings

#### External

Subcutaneous hemorrhage was observed in fetuses from all exposure groups with a higher incidence in the 1,000 mg/kg group; however, three of the five affected fetuses in the 1,000 mg/kg group were from the same dam (Table 11; (Appendix D), and the incidences were low and not significantly increased. Malformations observed in the vehicle control and exposed groups were limited to a single incidence each of meningocele, omphalocele, and bent right hind limb and to sporadic incidences of bent tail.

Table 11 Summary of Selected Fetal External Findings in the Prenatal Developmental Toxicity Study of Dimethylaminoethanol Bitartrate

| 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Total Number of Fetuses | 209 | 265 | 260 | 260
Number of Fetuses Examined | 209 | 265 | 260 | 260
Number of Litters Examined | 19 | 20 | 20 | 22
Body: General
Body, subcutaneous hemorrhage – [GF]
Fetuses | 1 (0.48) | 2 (0.75) | 1 (0.38) | 5 (1.92)
Litters | 1 (5.26) | 2 (10.00) | 1 (5.00) | 3 (13.64)
Extremities
Limb, hind, right, bent – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (0.38)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (4.55)
Tail, bent – [M]
Fetuses | 0 (0.0) | 1 (0.38) | 1 (0.38) | 2 (0.77)
Litters | 0 (0.00) | 1 (5.00) | 1 (5.00) | 1 (4.55)
Head
Head, meningocele – [M]
Fetuses | 1 (0.48) | 0 (0.0) | 0 (0.0) | 0 (0.0)
Litters | 1 (5.26) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Trunk
General, omphalocele – [M]
Fetuses | 0 (0.0) | 1 (0.38) | 0 (0.0) | 0 (0.0)
Litters | 0 (0.00) | 1 (5.00) | 0 (0.00) | 0 (0.00)

Upper row denotes number of affected fetuses (%), and lower row the number of affected litters (%).

Statistical analysis for litter data and for fetal data (without litter effect) performed by the Cochran-Armitage (trend) and the Fisher exact (pairwise) tests found no statistically significant trend or pairwise comparison, respectively.

Statistical analysis of fetuses with litter-based adjustments performed by mixed-effects logistic regression found no statistically significant trend or pairwise comparison.

[GF] = gross finding; [M] = malformation.

#### Visceral

There were single incidences of malformations in the heart of vehicle control and exposed groups that included large right atrium, thick bilateral ventricular wall, and ventricular septal defect (Table 12; Appendix D). Misshapen aortic valve, a malformation, was observed in all exposure groups at singular or low incidences. Visceral malformations in the major vessels of control and exposed groups were limited to single incidences of absent aortic arch, atresia of the innominate artery, and dilated pulmonary artery/trunk. Visceral variations occurred predominantly in the vessels and included absent or short innominate arteries, which are a common background variation; these were noted in both the vehicle control and exposed groups. The incidence of absent innominate artery in the 1,000 mg/kg group was significantly higher than in the control group; however, innominate artery variations are a common finding noted in approximately 5% of control rat fetuses.^75^

Table 12 Summary of Selected Fetal Visceral Findings in the Prenatal Developmental Toxicity Study of Dimethylaminoethanol Bitartrate

| 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Total Number of Fetuses | 209 | 265 | 260 | 260
Number of Fetuses Examined | 209 | 265 | 260 | 260
Number of Litters Examined | 19 | 20 | 20 | 22
Heart
Aortic valve, misshapen – [M]
Fetuses | 2 (0.96) | 1 (0.38) | 3 (1.15) | 1 (0.38)
Litters | 2 (10.53) | 1 (5.00) | 3 (15.00) | 1 (4.55)
Atrium, right, large – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (0.38)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (4.55)
Ventricle, bilateral, thick wall – [M]
Fetuses | 1 (0.48) | 0 (0.0) | 0 (0.0) | 0 (0.0)
Litters | 1 (5.26) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Ventricle, bilateral, ventricular septum defect – [M]
Fetuses | 1 (0.48) | 0 (0.0) | 0 (0.0) | 0 (0.0)
Litters | 1 (5.26) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Major Vessels
Aortic arch, absent – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 1 (0.38) | 0 (0.0)
Litters | 0 (0.00) | 0 (0.00) | 1 (5.00) | 0 (0.00)
Innominate artery, atresia – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (0.38)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (4.55)
Innominate artery, absent – [V]^a^
Fetuses | 3 (1.44)**^##^ | 4 (1.51) | 6 (2.31) | 12 (4.62)*^#^
Litters | 3 (15.79)* | 4 (20.00) | 4 (20.00) | 10 (45.45)*
Innominate artery, short – [V]
Fetuses | 6 (2.87) | 7 (2.64) | 8 (3.08) | 5 (1.92)
Litters | 4 (21.05) | 7 (35.00) | 6 (30.00) | 4 (18.18)
Pulmonary artery/trunk, dilated – [M]
Fetuses | 1 (0.48) | 0 (0.0) | 0 (0.0) | 0 (0.0)
Litters | 1 (5.26) | 0 (0.00) | 0 (0.00) | 0 (0.00)

Upper row denotes number of affected fetuses (%), and lower row the number of affected litters (%).

Statistical analysis for litter data and for fetal data (without litter effects) performed by the Cochran-Armitage (trend) and the Fisher exact (pairwise) tests. Statistical analysis of fetuses with litter-based adjustments performed by mixed-effects logistic regression.

* Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column).

** p ≤ 0.01.

^#^ Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column) in litter-based analysis of fetuses

^##^ p ≤ 0.01.

[M] = malformation; [V] = variation.

^a^ Historical incidence for control groups in prenatal developmental toxicity gavage studies: fetuses 27/1,326 (2.0%), range

1.4–2.8%; litters 22/104 (21.2%), range 15.8–27.8%.

#### Head

There were no exposure-related effects of dimethylaminoethanol bitartrate administration on the incidence of fetal head, specifically brain, abnormalities (Appendix D). Single or low incidences of nodulated costal cartilage (sixth, eighth, and ninth), a variation, were observed in vehicle control, 500 mg/kg, and 1,000 mg/kg groups. There was a negative trend in the incidences of total (sum of left, right, and bilateral) and full thoracolumbar ribs (malformation), whereas a significant increase in the incidence of left, bilateral, and total short thoracolumbar ribs (variation) was observed in the 1,000 mg/kg group compared to the control group, along with a significant positive trend.

Table 13 Summary of Selected Fetal Skeletal Findings in the Prenatal Developmental Toxicity Study of Dimethylaminoethanol Bitartrate

| 0 mg/kg | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Total Number of Fetuses | 209 | 265 | 260 | 260
Number of Fetuses Examined | 209 | 264 | 260 | 260
Number of Litters Examined | 19 | 20 | 20 | 22
Ribs
Costal cartilage, 6th right, nodulated – [V]
Fetuses | 1 (0.48) | 0 (0.0) | 0 (0.0) | 2 (0.77)
Litters | 1 (5.26) | 0 (0.00) | 0 (0.00) | 2 (9.09)
Costal cartilage, 8th right, nodulated – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 1 (0.38) | 0 (0.0)
Litters | 0 (0.00) | 0 (0.00) | 1 (5.00) | 0 (0.00)
Costal cartilage, 9th right, nodulated – [V]
Fetuses | 1 (0.48) | 0 (0.0) | 0 (0.0) | 0 (0.0)
Litters | 1 (5.26) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Supernumerary Rib
Thoracolumbar, left, full – [M]
Fetuses | 3 (1.44)* | 1 (0.38) | 0 (0.0) | 0 (0.0)
Litters | 3 (15.79)* | 1 (5.00) | 0 (0.00) | 0 (0.00)
Thoracolumbar, right, full – [M]
Fetuses | 3 (1.44) | 2 (0.76) | 1 (0.38) | 1 (0.38)
Litters | 3 (15.79) | 2 (10.00) | 1 (5.00) | 1 (4.55)
Thoracolumbar, bilateral, full – [M]
Fetuses | 1 (0.48) | 0 (0.0) | 0 (0.0) | 0 (0.0)
Litters | 1 (5.26) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Thoracolumbar, full, total – [M]
Fetuses | 7 (3.35)**^##^ | 3 (1.14) | 1 (0.38)*^#^ | 1 (0.38)*^#^
Litters | 6 (31.58)* | 3 (15.00) | 1 (5.00)* | 1 (4.55)*
Thoracolumbar, left, short – [V]
Fetuses | 23 (11.0)*^#^ | 32 (12.12) | 26 (10.0) | 45 (17.31)*^#^
Litters | 14 (73.68) | 17 (85.00) | 16 (80.00) | 17 (77.27)
Thoracolumbar, right, short – [V]
Fetuses | 16 (7.66) | 13 (4.92) | 9 (3.46)*^#^ | 16 (6.15)
Litters | 10 (52.63) | 10 (50.00) | 8 (40.00) | 10 (45.45)
Thoracolumbar, bilateral, short – [V]
Fetuses | 17 (8.13)**^##^ | 11 (4.17) | 24 (9.23) | 39 (15.0)*
Litters | 8 (42.11)* | 7 (35.00) | 11 (55.00) | 16 (72.73)*
Thoracolumbar, short, total – [V]^a^
Fetuses | 56 (26.79)**^##^ | 56 (21.21) | 59 (22.69) | 100 (38.46)**^#^
Litters | 17 (89.47) | 18 (90.00) | 18 (90.00) | 19 (86.36)
Skeletal: Skull
Number of Fetuses Examined | 100 | 128 | 126 | 128
Number of Litters Examined | 18 | 20 | 20 | 20
Skull
General, isolated ossification site – [V]
Fetuses | 1 (1.0) | 5 (3.91) | 3 (2.38) | 3 (2.34)
Litters | 1 (5.56) | 5 (25.00) | 2 (10.00) | 2 (10.00)
General, supernumerary site – [V]^b^
Fetuses | 1 (1.0)**^##^ | 3 (2.34) | 2 (1.59) | 13 (10.16)**^#^
Litters | 1 (5.56)** | 3 (15.00) | 2 (10.00) | 10 (50.00)**

Upper row denotes number of affected fetuses (%) and lower row the number of affected litters (%).

Statistical analysis for litter data and for fetal data (without litter effects) performed by the Cochran-Armitage (trend) and the Fisher exact (pairwise) tests. Statistical analysis of fetuses with litter-based adjustments performed by mixed-effects logistic regression.

* Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column).

** p ≤ 0.01.

^#^ Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column) in litter-based analysis of fetuses

^##^ p ≤ 0.01.

[V] = variation; [M] = malformation.

^a^ Historical incidence for control groups in prenatal developmental toxicity gavage studies: fetuses 247/1,324 (18.7%), range

9.9–26.8%; litters 83/104 (79.8%), range 66.7–91.3%.

^b^ Historical incidence for control groups in prenatal developmental toxicity gavage studies: fetuses 11/637 (1.73%), range

0.70–2.94%; litters 7/102 (6.86%), range 4.35–11.11%.

There was a significant increase in the number of supernumerary sites, or extra bones, in the skull (around the frontonasal suture) in 1,000 mg/kg fetuses relative to the control group (Table 13; (Appendix D) as well as a significant positive trend across all groups.