# Materials and Methods

## Overview of Prenatal Developmental Toxicity Study Designs

Prenatal developmental toxicity studies are conducted to ascertain if in utero exposure to a test agent results in embryo-fetal death, structural malformations/variations, growth retardation, or functional deficits that are not secondary to overt maternal toxicity. Overt maternal toxicity has been shown to impact normal embryo-fetal growth and development (e.g., excessively lower maternal body weight gains and lower fetal weights, increased maternal stress in mice, and cleft palate).^46-48^ The presence of maternal toxicity, however, should not negate a priori an apparent fetal response. Rather, given the maternal/embryo-fetal interrelationship, maternal responses should be considered when interpreting fetal findings. Pregnant animals should be administered the highest feasible dose levels of test agent (or the limit dose) to achieve maximal dam and fetal exposure and sufficiently challenge the test system to identify potential developmental hazards.^49^

The conduct of a dose range-finding study helps determine dose selection when the potential for test agent-induced maternal toxicity is unknown, can provide preliminary information on embryo-fetal outcomes (e.g., postimplantation loss, changes in fetal weight, external defects), and informs the prenatal developmental toxicity study design. In the prenatal developmental toxicity study, fetal examination is expanded to include examination of the fetal viscera, head (soft tissue and skeletal components), and the skeleton for osseous and cartilaginous defects. Abnormalities are categorized in one of two groups: (1) malformations that are permanent structural changes that could adversely affect survival, development, or function; and (2) variations that are a divergence beyond the usual range of structural constitution but might not adversely affect survival or health,^47^ consistent with that described by Makris et al.^50^ The general study design for the dose range-finding and prenatal developmental toxicity studies in the rat is presented in Figure 2.

Figure 2

Design of a Dose Range-finding and Prenatal Developmental Toxicity Study in Rats

^a^Animals are exposed once daily from gestation day (GD) 6 to GD 20 and necropsied on GD 21.

^b^All fetuses are examined externally (including inspection of the oral cavity). Fetuses in the prenatal developmental toxicity study are also examined for visceral and skeletal effects with approximately 50% of the heads examined for soft tissue alterations.

## Procurement and Characterization

### Dimethylaminoethanol Bitartrate

Dimethylaminoethanol bitartrate (DMAE) was obtained from Bayville Chemical Supply Company, Inc. (Deer Park, NY) in one lot (159AK) that was used in the dose range-finding and prenatal developmental toxicity studies (Appendix A). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) for the study laboratory at Southern Research (Birmingham, AL). Lot 159AK of the chemical, a white crystalline powder, was identified as dimethylaminoethanol bitartrate using Fourier transform infrared (FTIR) and proton and carbon-13 nuclear magnetic resonance spectroscopy. The exact mass for dimethylaminoethanol and tartaric acid was determined using ultra high-performance liquid chromatography (UHPLC) coupled with time-of-flight mass spectrometry (TOF-MS) detection. In addition, the melting point of the bulk chemical was determined.

The moisture content of lot 159AK was measured by a desorption type Karl Fischer analysis and by thermogravimetric analysis (TGA); these procedures were conducted by Robertson Microlit Laboratory (Ledgewood, NJ). The purity of lot 159AK was determined by Galbraith Laboratories, Inc. (Knoxville, TN) using elemental analyses and by the analytical chemistry laboratory. RTI initially used UHPLC/TOF-MS with a hydrophilic interaction liquid chromatography (HILIC) gradient in the positive mode for dimethylaminoethanol and in the negative mode for tartaric acid; they subsequently used gas chromatography (GC) with MS detection. RTI assayed the bulk chemical for volatile organic impurities using two GC systems with flame ionization detection (FID).

The Karl Fischer analysis indicated approximately 12% water, and TGA results indicated an estimated maximum water content not greater than 3.5%, as calculated from the mass lost in the temperature range matching the boiling point of water. Elemental analyses for carbon, hydrogen, nitrogen, and oxygen were consistent with the structural composition of dimethylaminoethanol bitartrate and theoretical values. UHPLC/TOF-MS indicated one major peak in chromatograms accounting for greater than 99.9% of the total peak area relative to either the dimethylaminoethanol or tartaric acid peaks. GC/MS indicated one major peak accounting for 100% of the total peak area; the spectrum was consistent with a library reference spectrum.^51^ A residual solvent screening assay using GC/FID by a second system tentatively identified the presence of ethanol at 0.325% (w/w). The overall purity of lot 159AK was determined to be 96% or greater.

Stability studies of lot 159AK were conducted using the same HILIC gradient UHPLC/TOF-MS system used for the bulk chemical purity assessment. Results indicated that both dimethylaminoethanol and the counterion tartaric acid were stable in the bulk chemical for at least 14 days when stored in amber glass vials sealed with Teflon^®^-lined caps at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature in sealed amber glass bottles. Reanalyses of the bulk chemical were performed prior to the dose range-finding study and after the prenatal developmental toxicity study using FTIR spectroscopy (dose range-finding study only) and GC/FID by a fourth system—no degradation of the bulk chemical was detected.

### Sterile Water for Irrigation

The sterile water vehicle was obtained from Baxter Healthcare Corporation (Cleveland, MS) in two lots (G105999 and G110783). Lot G10599 was used in the dose range-finding study, and lot G110783 was used in the prenatal developmental toxicity study.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared once for each study by mixing dimethylaminoethanol bitartrate with sterile water to give the required concentrations (Appendix D). The dose formulations were stored at room temperature in sealed amber glass bottles for up to 42 days.

The analytical chemistry laboratory used GC/FID to evaluate syringeability of a 300 mg/mL formulation using a 22-gauge gavage needle and stability of a 10 mg/mL formulation. Syringeability was confirmed, and stability was confirmed for at least 42 days for dimethylaminoethanol formulations stored in sealed clear glass bottles both refrigerated and up to room temperature and for 3 hours under simulated animal room conditions.

Additional stability studies of formulations of dimethylaminoethanol bitartrate in sterile water were performed to monitor the relative stability of the tartaric acid counterion and the pH of the formulations. Two formulations (25.0 and 22.5 mg/mL) of dimethylaminoethanol bitartrate in sterile water were prepared for direct comparison to standards of tartaric acid at concentrations equivalent to those present in the formulations. After dilution into the range of a validated analytical method, a 300 mg/mL formulation was also analyzed using HPLC. Formulations were determined to have a stable tartaric acid concentration for at least 42 days. The pH of the formulations across the concentration range 2.5 to 300 mg/mL was between 3.4 and 3.6; the 10 mg/mL formulation suggests that the pH did not change over the period of 42 days when stored either refrigerated or at room temperatures.

Periodic analyses of the dose formulations of dimethylaminoethanol bitartrate were conducted by the analytical chemistry laboratory using GC/FID. During the dose range-finding study, the dose formulations were analyzed once; all three of the dose formulations were within 10% of the target concentrations. Animal room samples of these dose formulations were also analyzed, and all three were within 10% of the target concentrations. During the prenatal developmental toxicity study, the dose formulations were analyzed once; all three dose formulations analyzed were used and all three animal room samples were within 10% of the target concentrations.

## Animal Source

Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) for use in the dose range-finding and prenatal developmental toxicity studies (Table 1). Sexually mature (12 to 13 weeks old) females were time-mated overnight at the vendor and were received on gestation day (GD) 1 or 2 for both the dose range-finding and prenatal developmental toxicity studies. GD 0 was defined as the day positive evidence of mating was observed.

Table 1 Experimental Design and Materials and Methods in the Dose Range-finding and Prenatal Developmental Toxicity Gavage Studies of Dimethylaminoethanol Bitartrate in Rats

Dose Range-finding Study | Prenatal Developmental Toxicity Study
Study Laboratory
Southern Research (Birmingham, AL) | Southern Research (Birmingham, AL)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats
Animal Source
Envigo (formerly Harlan Laboratories, Inc.) (Indianapolis, IN) | Envigo (formerly Harlan Laboratories, Inc.) (Indianapolis, IN)
Day of Arrival
February 5, 2014 (GD 2) | April 9, 2014 (GD 1 or 2) April 11, 2014 (GD 1 or 2) April 16, 2014 (GD 1 or 2)
Average Age on Arrival
12 weeks | 12 to 13 weeks
Weight Range at Randomization
224.8–262.3 g | 207.5 to 260.6 g on GD 3
Calendar Day of First Dose and Last Dose
GD 6 (February 9, 2014) and GD 20 (February 24, 2014) | GD 6 (April 13, 14, 15, 16, or 20, 2014) and GD 20 (April 27, 28, 29, 30, or May 4, 2014)
Duration of Dosing
GD 6 to 20, once daily | GD 6 to 20, once daily
Size of Study Groups
10 time-mated females | 25 time-mated females
Method of Randomization and Identification
Time-mated animals were uniquely identified on day of receipt by indelible ink tail marking and assigned to one of four exposure groups by stratified randomization of GD 3 body weights using Instem Provantis^®^ (version 8) electronic data collection system. Each animal was assigned a unique animal number in Provantis. This number was linked to the respective tattoo, and all data collected during the study was associated with the Provantis animal number. | Same as dose range-finding study
Animals per Cage
1 | 1
Diet
Irradiated NIH-07 0.5-inch pellet Certified Rodent Diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum | Same as dose range-finding study
Water
Tap water (Birmingham Water Works Co., Birmingham, AL, municipal supply) via automatic watering system, available ad libitum | Same as dose range-finding study
Cages
Solid bottom polycarbonate cages (Lab Products, Inc., Seaford, DE), changed weekly | Same as dose range-finding study
Bedding
Certified irradiated Sani-Chips^®^ hardwood cage bedding (P.J. Murphy Forest Products Corporation, Montville, NJ), changed weekly | Same as dose range-finding study
Cage Filters
Reemay^®^ spun-bonded polyester (Andico, Birmingham, AL), changed every 2 weeks | Same as dose range-finding study
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks | Same as dose range-finding study
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as dose range-finding study
Doses
0, 250, 500, or 1,000 mg/kg in sterile water (dosing volume 5 mL/kg) | 0, 250, 500, or 1,000 mg/kg in sterile water (dosing volume 5 mL/kg)
Type and Frequency of Observation of Dams
Observed for viability twice daily (cageside) from GD 3 through GD 20 Clinical observations (out of cage) were performed at least once during the pre-study period and at least once daily while on study (1 to 3 hours postdose). Animals were weighed daily beginning on GD 3. Feed consumption was recorded at 3-day intervals from GD 6 through GD 21. | Observed for viability twice daily (cageside) from GD 3 through GD 20. Clinical observations (out of cage) were performed at least once during the pre-study period and at least once daily while on study (1 to 3 hours postdose). Animals were weighed on the day of arrival, on GD 3, and on GD 6 through GD 21. Feed consumption was recorded at 3-day intervals from GD 6 through GD 21.
Primary Method of Euthanasia
100% CO_2_ (adults) or intraperitoneal injection of a solution containing sodium pentobarbital followed by bilateral pneumothorax and/or decapitation (fetuses) | 100% CO_2_(adults) or decapitation or intraperitoneal injection of a solution containing sodium pentobarbital followed by bilateral pneumothorax and/or decapitation (fetuses)
Necropsy and Postmortem Evaluation of Females
On GD 21, terminal body weights and gravid uterine weights were recorded, and the uterine contents examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live or dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained with a 10% aqueous solution of ammonium sulfide to visualize potential evidence of implantation sites. There were no early removals. | On GD 21, terminal body, liver, and gravid uterine weights were recorded. Uterine contents were examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live or dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained with a 10% aqueous solution of ammonium sulfide to visualize potential evidence of implantation sites. For animals removed early, gross necropsy including an examination of the thoracic and abdominal viscera was performed. The uterus of each female was examined to determine pregnancy status, or, if no evidence of pregnancy, stained to visualize possible early implantation sites.
Fetal Evaluation
Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities that included inspection of the oral cavity for cleft palate. | Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities including inspection of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were euthanized and then examined for visceral morphological abnormalities by fresh dissection. The sex of each fetus was confirmed by internal examination. The heads from approximately one half of the fetuses in each litter were fixed, sectioned, and examined. All fetuses were eviscerated, fixed, stained, and examined for visceral and skeletal developmental variations, malformations, or other morphological findings.

GD = gestation day.

## Animal Health Surveillance

Disease screening was not conducted; however, rats were obtained from a commercial colony free of the following rat pathogens: Sendai virus, pneumonia virus of mice, sialodacryoadenitis virus, Kilham rat virus, Toolan’s H1 virus, rat minute virus, reovirus, rat theilovirus, lymphocytic choriomeningitis virus, hanta virus, mouse adenovirus, rat parvovirus, Mycoplasma pulmonis, and Pneumocystis carinii.

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Southern Research Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Experimental Design

In both dimethylaminoethanol bitartrate studies, time-mated rats were housed individually, provided NIH-07 feed and water ad libitum, and observed at least twice daily for viability (morning and afternoon). Clinical observations were recorded on GD 3 (prenatal developmental toxicity study only), and on GD 6 through GD 21 until removal, typically twice daily (at the time of dose administration and cage side postdose). Dams in the dose range-finding study were weighed daily from GD 3 through GD 21, and those in the prenatal developmental toxicity study were weighed on the day of arrival, on GD 3, and daily from GD 6 through GD 21. Feed consumption was recorded for GD 6 to 9, GD 9 to 12, GD 12 to 15, GD 15 to 18, and GD 18 to 21. Details of the study design—including animal source and identification, diet, water, husbandry, environmental conditions, euthanasia, necropsy, and fetal evaluations—are summarized in Table 1. Information on feed composition and contaminants are provided in Appendix B.

On GD 21, rats were weighed, euthanized with CO_2_ inhalation, and examined for gross lesions of the thoracic and abdominal cavities. The liver and gravid uterus were excised and weighed (liver for the prenatal developmental toxicity study only), and any placental findings were recorded. The numbers of uterine implantation sites and corpora lutea visible on the surface of each ovary were recorded. Uterine contents were examined for pregnancy status, and the number and location of all live and dead fetuses (a live fetus is defined as one that responds to stimuli; a dead fetus is defined as a term fetus that does not respond to stimuli and is not markedly autolyzed) and resorptions were recorded. Resorptions were classified as early or late. Early resorptions included a conceptus characterized by a grossly necrotic mass that had no recognizable fetal form or presence of nidation sites (“pregnant by stain”). Late resorptions were characterized by grossly necrotic but recognizable fetal forms with placental remains visible.^53;^ ^54^ Postimplantation loss was calculated as the number of dead plus resorbed conceptuses divided by the total number of implantations (multiplied by 100). For each uterus with no macroscopic evidence of implantation, the uterus was stained with 10% (v/v) ammonium sulfide to visualize any possible early implantation sites.^55^

Adult females that were euthanized moribund, delivered early, or found dead received a gross necropsy that included an examination of the thoracic and abdominal viscera for evidence of dosing trauma or toxicity. The uterus of each female was examined and stained, if necessary, to determine pregnancy status. Dams were not retained for further examination.

### Dose Range-finding Study

Time-mated rats were individually identified by tail marking and randomized by GD 3 body weight stratification into four groups (vehicle control, low, mid, or high) using Southern Research’s Instem™ Provantis^®^ (version 8) electronic data collection system.

Groups of 10 time-mated female rats were administered 0 (vehicle control), 250, 500, or 1,000 mg dimethylaminoethanol bitartrate/kg body weight per day (mg/kg/day) calculated from the most recent body weight, in sterile water by gavage from GD 6 to GD 20. Vehicle control animals received sterile water alone; the dosing volume was 5 mL/kg body weight.

A high dose of 1,000 mg/kg dimethylaminoethanol bitartrate was selected for the dose range-finding study because 1,000 mg/kg is the limit dose recommended by the Organisation for Economic Co-operation and Development (OECD) for prenatal developmental toxicity studies.^49^

On GD 21, fetuses were removed from the uterus, individually weighed (live fetuses only), and examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were euthanized by decapitation or with intraperitoneal injection of a commercially available solution containing sodium pentobarbital followed by bilateral pneumothorax and/or decapitation. Fetuses were not retained following completion of the external examination.

### Prenatal Developmental Toxicity Study

On receipt (GD 1 or 2), time-mated rats were individually identified by tail marking and randomized by GD 3 body weight stratification into four groups (vehicle control, low, mid, or high) using Southern Research’s Instem™ Provantis^®^ (version 8) electronic data collection system. Dams were received in three groups, at least 2 days apart, to allow for a staggered study start.

Groups of 25 time-mated female rats were administered 0 (vehicle control), 250, 500, or 1,000 mg dimethylaminoethanol bitartrate/kg/day (based on the most recent body weight) in sterile water by gavage from GD 6 to GD 20. Vehicle control animals received sterile water alone; the dosing volume was 5 mL/kg body weight.

On GD 21, fetuses were removed from the uterus, and live fetuses individually weighed. The uteri of animals that did not appear pregnant were examined for nidations (implantation sites) by staining with 0.5% ammonium sulfide.^55;^ ^56^ All fetuses were examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were subsequently euthanized by intraperitoneal injection of sodium pentobarbital. Fetal sex was confirmed by inspection of gonads in situ. All fetuses were examined for soft tissue alterations under a stereomicroscope.^57;^ ^58^ The heads were removed from approximately half of the fetuses in each litter, fixed in Bouin’s solution, and subsequently examined by free-hand sectioning.^59^ This technique precludes skeletal evaluations of the skull; therefore, remaining heads and all fetuses were eviscerated, fixed in ethanol, macerated in potassium hydroxide, stained with alcian blue and alizarin red, and examined for subsequent cartilage and osseous alterations.^56;^ ^60^ External, visceral, and skeletal fetal alterations were recorded as developmental variations or malformations.

## Statistical Methods

In both the dose range-finding study and the main study, statistical analyses were performed on data from pregnant females that survived until the end of the study and were examined on GD 21 and from live fetuses. Statistical analyses were performed using SAS 9.3 (SAS Institute, Cary, NC).

### Descriptive Statistics

Maternal Parameters: Maternal body weights were measured daily starting at GD 3 and reported as means. Terminal maternal body weights at GD 21 were adjusted for gravid uterine weight by subtracting the gravid uterine weight from the dam’s body weight. Body weight gains were calculated over each 3-day interval and from GD 6 to GD 21. Daily feed consumption was averaged over each 3-day interval and from GD 6 to GD 21. These continuous variables, in addition to gravid uterine weights, other organ weights, hematology, and clinical chemistry were summarized with means and standard errors.

Placental and Fetal Parameters: Data on uterine contents are reported as means and standard errors of counts per dam/litter (corpora lutea, implants, resorptions, dead fetuses) and as total numbers of occurrences (resorptions, dead fetuses). Data from females that were not pregnant or that did not survive to the end of the study were not included. Postimplantation loss is calculated as a percentage of the number of implants per dam. Fetal findings are reported as means and standard errors of counts per litter (numbers of live fetuses, male fetuses, and female fetuses), means and standard errors of litter means (fetal weight, male fetal weight, and female fetal weight), and total numbers of occurrences (total number of live fetuses). In addition, several calculated variables are reported, including the percentage of live male fetuses per litter.

Incidences of morphological findings from the gross, external, visceral, skeletal, and head examinations of pathology of placentae and fetuses are presented as number and percentage of affected fetuses and as number and percentage of affected litters.

### Analysis of Maternal Parameters and Uterine Contents

Maternal organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^61^ and Williams.^62;^ ^63^ Non-normally distributed variables, such as feed consumption and uterine content endpoints, were analyzed using the nonparametric multiple comparison methods of Shirley^64^ (as modified by Williams^65^) and Dunn.^66^ For normally distributed and non-normally distributed variables, the Jonckheere test^67^ was used to assess the significance of dose-related trends at p < 0.01 to determine whether a monotonic trend-sensitive test (the Williams or Shirley test) was more appropriate than a test that does not assume a monotonic dose-related trend (the Dunnett or Dunn test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^68^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

Fetal body weights were analyzed using mixed-effects linear models, with litter as a random effect to account for potential within-litter correlations. To test for a linear trend, the numerical values of dose were used, and the fit to a linear model was evaluated. For pairwise comparisons with the control group, a second mixed-effects model used dose as a categorical variable, followed by the Dunnett^61^ and Hsu^69^ multiple comparisons tests.

### Analysis of Incidences of Gross Pathology and Morphology Findings

Incidences of gross findings, malformations, and variations in the fetuses were summarized and analyzed as the number of litters affected and as the number of fetuses affected. Incidences of gross findings, malformations, and numbers of litters affected were analyzed using the Cochran-Armitage trend test^70^ and Fisher’s exact test.^71^ The numbers of fetuses affected were analyzed using mixed-effects logistic regression in which the litter was a random effect to account for potential litter effects.^72-74^ For each fetal finding, an initial mixed-effects logistic regression model used the numerical value of dose to assess the significance of a dose-related trend; a subsequent logistic regression model incorporated dose as a categorical variable to compare each exposure group with the control group. To conduct the mixed-effects logistic regression analyses, at least one finding was required per exposure group, and the correlation matrix describing the relationship between litters was required to be “positive definite.” If the mixed-effects logistic regression failed to converge or did not meet the specified criteria, two separate analyses were used to bracket the true p value. The Cochran-Armitage trend test and Fisher exact test were used with litter as the experimental unit to calculate the upper limit for the true p value and with fetus as the experimental unit to calculate the lower limit for the true p value.

## Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP developmental and reproductive toxicity studies. However, historical control data are often helpful in interpreting potential exposure-related effects, particularly for uncommon fetal findings that occur at very low incidence. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Factors that could affect the background incidences of fetal findings at a variety of anatomical sites are diet, sex, strain/stock, route of exposure, study type, and laboratory that conducted the study. The NTP historical control database for teratology studies contains all fetal evaluations (e.g., teratology studies or modified one-generation studies) for each laboratory. In general, the historical control database for a given study includes studies using the same route of administration and study design. Historical control data for rats in this Developmental and Reproductive Toxicity Technical Report represent data from gavage studies conducted at Southern Research. The concurrent controls are included in the historical control data set. NTP historical controls are available online at https://ntp.niehs.nih.gov/go/historical_controls.

## Quality Assurance Methods

The dose range-finding and prenatal developmental toxicity studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). Records from these studies were submitted to the NTP Archives. The prenatal developmental toxicity study was audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the final study data tables for the dose range-finding and prenatal developmental toxicity studies and a draft of this NTP Developmental and Reproductive Toxicity Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.