# Introduction

Figure 1

Dimethylaminoethanol Bitartrate (CASRN: 5988-51-2; Chemical Formula: C_4_H_11_NO • C_4_H_6_O_6_; Molecular Weight: 239.23)

Synonyms: 2-Dimethylaminoethanol bitartrate; 2-dimethylaminoethanol tartrate; dimethylethanolamine bitartrate; N,N-dimethylethanolamine- tartaric acid salt; ethanol, 2-(dimethylamino)-, [R(R*,R*)]-2,3-dihydroxybutanedioate; ethanol, 2-(dimethylamino)-, tartrate.

## Chemical and Physical Properties

Dimethylaminoethanol bitartrate, a salt of dimethylaminoethanol, is produced from dimethylaminoethanol and tartaric acid. Dimethylaminoethanol bitartrate is a white powder with a molecular weight of 239.23 g/mol and a melting point range of 109°–113°C; it is also soluble in water.^1;^ ^2^

There is limited information available on the bitartrate form, but dimethylaminoethanol, the free base, is a colorless liquid with a molecular weight of 89.136 g/mol, a melting point of −65°C, and a boiling point of 134.1°C.^3^ Dimethylaminoethanol has a density of 0.8866 g/cm^3^(at 20°C), a log K_OW_(octanol:water partition coefficient) of −0.55 (at 23°C), and a vapor pressure of 21 mm Hg torr (at 20°C). It has also been reported to have an amine or fishy odor. Dimethylaminoethanol is moderately flammable.^3^

## Production, Use, and Human Exposure

A production volume of 100 to 250 million pounds was reported for dimethylaminoethanol in 2015 that was based on information submitted under the 2016 Toxic Substances Control Act Inventory Update Rule.^4^ Dimethylaminoethanol was also included in the 2004 Organisation for Economic Co-operation and Development (OECD) List of High Production Volume Chemicals,^5^ which included chemicals produced at more than 1,000 tons per year. The U.S. Environmental Protection Agency (EPA) Chemical Data Reporting (CDR) database^6^ listed eight United States-based industries producing dimethylaminoethanol; two of those companies reported annual production of 38,000 and 79,000 pounds dimethylaminoethanol.^6^

Dimethylaminoethanol is used in a variety of industrial and consumer applications, including as a catalyst in the curing of epoxy resins and polyurethanes, as an inhibitor of corrosion, and as an amino resin stabilizer. Dimethylaminoethanol is also used as a chemical intermediate in the synthesis of antihistamines, local anesthetics, dyes, textiles, and emulsifiers/solubilizers in water-based paints.^3^ In accordance with the OECD Screening Information Data Set, it is estimated that 50% of dimethylaminoethanol produced is used in the manufacturing of flocculants for wastewater treatment; 20% in the manufacturing of flexible and rigid polyurethane foams and lacquers; 20% in the manufacturing of water-based paints and surface coatings; and 10% to produce ion exchange resins, pharmaceuticals, and corrosion inhibitors.^7^

Occupational exposure to dimethylaminoethanol is believed to primarily involve workers in the spray painting and beverage can lacquering industries. There is some concern for the release of dimethylaminoethanol into the environment from these industrial sources.^8^

Nonoccupational exposure to dimethylaminoethanol can occur through the consumption of squid, sardines, and other fatty fish.^9^ Dimethylaminoethanol can also be released from sealants, architectural coatings, furniture and cabinet coatings, polyurethane foam cushions, and carpets in homes, buildings, and vehicles;^10;^ ^11^ however, the primary concern for nonoccupational exposure is through pharmaceuticals and dietary supplements.

Dimethylaminoethanol is a close structural analog of choline (N,N,N-trimethylaminoethanol), an essential nutrient. Dimethylaminoethanol supplies the brain with choline, where it is acetylated by choline acetylase to form acetylcholine.^10^ Dimethylaminoethanol salts (e.g., p-acetamidobenzoate) have been used to treat central nervous system disorders in humans, specifically those considered to be associated with decreased cholinergic neuron function.^12^ Dimethylaminoethanol salts have also been used to manage learning and behavioral problems, Huntington’s chorea, chronic fatigue, and neurasthenia.^3;^ ^10;^ ^13^ The prescription drug Deaner^®^ (deanol p-acetamidobenzoate) was used in the United States for more than 20 years to treat learning and behavioral problems in children, but was withdrawn from the market in 1983 due to better alternatives becoming available. The dimethylaminoethanol chemical structure is also part of many different pharmaceutical formulations, including a variety of antihistamines, antiemetics, local anesthetics, and tamoxifen.^9^

A number of dietary supplements on the market contain dimethylaminoethanol, most commonly in the form of dimethylaminoethanol bitartrate, and these supplements are purported to improve memory and general cognitive function. The recommended dosage for these supplements varies between products, with recommended adult doses ranging from 100 to 500 mg dimethylaminoethanol/day. One dimethylaminoethanol bitartrate supplement currently on the market contains 351 mg dimethylaminoethanol bitartrate, which corresponds to approximately 130 mg dimethylaminoethanol.^14^ Dietary supplements containing dimethylaminoethanol are also marketed to treat symptoms of attention deficit hyperactivity disorder (ADHD) in children and on average contain 100 mg dimethylaminoethanol (as dimethylaminoethanol bitartrate).^15;^ ^16^

## Regulatory Status

No regulatory limits for dimethylaminoethanol exposure have been established by NIOSH or EPA. Individual industrial companies have established workplace exposure limits for dimethylaminoethanol; for example, DuPont has an 8-hour time-weighted average of 2 ppm for dimethylaminoethanol.^9^ Federal regulations currently applicable to dimethylaminoethanol include the following: 40 CFR Part 60 [Subpart YYY–Standards of Performance for Volatile Organic Compounds (VOC) Emissions from Synthetic Organic Chemical Manufacturing Industry (SOCMI) Wastewater], which regulates the emission of volatile organic compounds (VOCs) from wastewater; 40 CFR § 63.100ff (Subpart F–National Emission Standards for Organic Hazardous Air Pollutants from the Synthetic Organic Chemical Manufacturing Industry), which regulates air pollution emitted by chemical manufacturers that produce dimethylaminoethanol (or mixtures containing dimethylaminoethanol); 21 CFR § 173.20 [Secondary Direct Food Additives Permitted in Food for Human Consumption (Subpart A–Polymer Substances and Polymer Adjuvants for Food Treatment)], which regulates membranes used for food packaging that were produced by reactions with dimethylaminoethanol; and 21 CFR § 175.300 (Indirect Food Additives: Adhesives and Components of Coatings), which states that dimethylaminoethanol, when used in coating emulsions, can be used as an adjuvant at no more than 2% (by weight).

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Data on absorption, distribution, metabolism, and excretion of dimethylaminoethanol bitartrate could not be located in the literature, and data for dimethylaminoethanol or other dimethylaminoethanol salts or esters in the literature are limited. Briefly, in male Wistar rats, following an intravenous dose of 11 mg/kg (120 mmol/kg) [^14^C]dimethylaminoethanol or 30 mg/kg (120 mmol/kg) cyprodenate, 0.16% and 0.2%, respectively, of the administered dose were measured in the plasma 6 minutes after dosing.^17^ Only 33% of the administered dose was eliminated in urine by 24 hours. The N-oxide of dimethylaminoethanol was the primary urinary metabolite in rodents, constituting 13.5% of the dose eliminated in urine within 24 hours. In another study in rats, following an intravenous dose of 30 mg/kg (0.13 mmol/kg) [^14^C]cyprodenate maleate, the cyclohexylpropionic acid ester of dimethylaminoethanol, approximately 2.41%, 1.30%, and 0.20% of the dose was found in the liver, brain, and plasma, respectively, 5 minutes after dosing. In male mice, 10 minutes after an intraperitoneal dose of 300 mg/kg (3.30 mmol/kg) dimethylaminoethanol, approximately 280 nmol dimethylaminoethanol/g plasma was detected.^18^ Daily oral exposures (duration not provided) of chinchilla rabbits to dimethylaminoethanol as deanol acetamidobenzoate (0.48 μg, 1.8 nmol) or dimethylaminoethanol (10.4 μg, 4.5 nmol), resulted in plasma concentrations of 6 to 7 μM (1.6 to 1.9 μg/mL) deanol acetamidobenzoate or 12 to 18 μM (1.1 to 1.6 μg/mL) dimethylaminoethanol. The chemical could not be detected in the plasma 36 hours after the end of the treatment period. Concentrations in the cerebrospinal fluid were similar to measurements in the plasma.^19^

NTP investigated the absorption, distribution, metabolism, and excretion of dimethylaminoethanol in male and female Wistar Han rats and B6C3F1/N mice.^20^ Within 24 hours following gavage administration of 10, 50, or 500 mg/kg in rats, 57–62% of the administered dose was excreted in urine, 4–5% was expired as CO_2_, and <1% was recovered in feces and as volatile organic compounds demonstrating that dimethylaminoethanol was well absorbed and rapidly excreted. A significant amount of the administered dose was retained in tissues with 34%, 30%, and 24% of the 10, 50, and 500 mg/kg doses, respectively, recovered 24 hours after administration. Following a single oral dose of 500 mg/kg in rats, [^14^C]dimethylaminoethanol-derived radioactivity was highest 2 hours after administration and declined over time with 84%, 24%, 15%, and 13% recovered at 2, 24, 72, and 168 hours, respectively. Of the tissues examined, liver, kidney, lung, and thyroid gland contained the highest concentrations; tissue-to-blood ratio was higher than 1.0 in all examined tissues. Excretion in mice was somewhat different than in rats, with increasing dose (10, 50, and 500 mg/kg), the administered dose recovered at 24 hours in urine increased (16%, 18%, and 43%), expired as CO_2_ decreased (22%, 16%, and 13%), and that remaining in tissues decreased. The tissues with the highest levels of radioactivity were the liver, kidney, thyroid gland, lung, spleen, adipose, and uterus.

Urinary products identified following gavage administration of dimethylaminoethanol were the N-oxide metabolite and unmetabolized parent compound; the amounts of each depended on the dose, sex, and species. N,N-dimethylglycine was identified as a minor metabolite; dimethylamine and N,N-dimethylnitrosamine were not detected. As the dose increased, the concentration of parent compound generally increased compared with that of the N-oxide, except in male rats, suggesting saturation of metabolism. In male rats, the N-oxide metabolite was not detected at the low dose; however, at the higher doses, male rats produced more N-oxide than male mice and female rats and mice.^20^

Following administration of 500 mg/kg dimethylaminoethanol in male Wistar Han rats, serum choline levels were moderately elevated within 12 hours of administration.^20^ To understand the effects of choline disposition by dimethylaminoethanol, male and female rats were given three consecutive daily gavage doses of 100 or 500 mg/kg dimethylaminoethanol prior to administration of a single dose of 100 mg/kg [^14^C]choline. Only modest effects on choline disposition occurred. In an investigation by Schlenk^21^ following intracerebral injection of [^14^C]dimethylaminoethanol in rats, brain levels of phosphatidylethanolamine were found to increase over the 7-hour observation period and were 10- to 40-fold higher than levels of phosphodimethylethanolamine. Analysis of brain tissue from mice administered [^14^C]dimethylaminoethanol or p-chlorophenoxyacetate, a dimethylaminoethanol derivative, indicated the presence of phosphoryl-dimethylaminoethanol and phosphatidyl-dimethylaminoethanol; phosphatidyl-dimethylaminoethanol is believed to be the end-metabolite of dimethylaminoethanol.^22^ Mice administered dimethylaminoethanol had increased concentrations and rate of turnover of free choline in the blood and kidneys.^9^ Jope and Jenden^23^ reported increased choline concentrations in the plasma and brain of rats treated with dimethylaminoethanol. The extent to which dimethylaminoethanol is methylated and substituted into acetylcholine is not well understood; however, it has been suggested that once it crosses the blood-brain barrier, dimethylaminoethanol is methylated to form choline and subsequently incorporated into acetylcholine.^9^ Dimethylaminoethanol is reported to undergo metabolism via the phospholipid cycle, resulting in the production of phosphoryldimethylethanolamine and glycerophosphatidylcholine.^17^

### Humans

In a study using human volunteers, 33% of an injected dose of 1 g (10 mmol) dimethylaminoethanol was excreted unchanged.^24^ The investigators proposed that the remaining compound could have been demethylated to ethanolamine and used in normal metabolic pathways.

## Developmental and Reproductive Toxicity

### Experimental Animals

Choline is an essential nutrient; however, mammals are limited in their ability to synthesize choline and, therefore, much of it is acquired through dietary sources. Choline is required for many biological processes, in particular nervous system development, and choline deficiency has been associated with the development of neural tube defects (NTDs).^25;^ ^26^ As dimethylaminoethanol is a structural analog of choline, there is potential for dimethylaminoethanol to disrupt choline uptake and metabolism and thereby interfere with biological processes such as development.

Pregnant Sprague Dawley rats fed a choline-deficient diet supplemented with 1% N-methylaminoethanol or 1% dimethylaminoethanol (10,000 mg/kg feed) from gestational day (GD) 6 to postnatal day (PND) 14 had significantly reduced offspring survival compared to pregnant rats supplied standard lab chow.^27^ Despite no effects on pregnancy progression, litter size, or pup body weight, only 18/253 pups from exposed dams survived to at least PND 3, whereas pups from control dams survived to at least PND 15. Pups from dams fed the dimethylaminoethanol-supplemented diet had increased levels of glycogen and fatty infiltration in their livers; dimethylaminoethanol (72.2 ± 12.7 nmol/g) was measured in the brains of these pups as well. Choline and acetylcholine levels were increased (53% and 36%, respectively) in the brains of pups from dams fed the dimethylaminoethanol-supplemented diet relative to dams fed the choline-deficient diet.

Exposure to dimethylaminoethanol via inhalation for 90 days did not induce any histopathologic changes in the gonads of rats.^9^

Inhalation exposure to dimethylaminoethanol (10, 30, or 100 ppm) induced maternal toxicity in pregnant Fischer 344 rats, as indicated by decreases in body weight (30 and 100 ppm) and ocular effects (30 and 100 ppm).^28^ Reported gestational effects included significant decreases in the number of viable implants per litter, the percentage of live fetuses per litter, and litter size (all evident at the lowest concentration tested, 10 ppm), as well as a significant decrease in the percentage of male fetuses in rats exposed to 30 ppm dimethylaminoethanol.

Skeletal alterations were observed in the fetuses of pregnant Fischer 344 rats exposed to 10 to 100 ppm dimethylaminoethanol via inhalation from GD 6 to GD 15.^29^ Recorded skeletal variations were sporadic and included increased incidences of split cervical centra 1, 2, 3, and/or 4, and bilobed thoracic centrum 1. Decreased incidences of poorly ossified cervical centrum 6, bilobed thoracic centrum 9, bilobed sternebra 5, and unossified proximal phalanges of the forelimb were also reported. A no-observed-adverse-effect level (NOAEL) of 100 ppm or greater was estimated for embryo-fetal toxicity and teratogenicity, whereas a NOAEL of 10 ppm was estimated for maternal toxicity.

Exposure of neurulating mouse embryos (collected at GD 9) to dimethylaminoethanol (0, 250, 375, 500, or 750 µM) in vitro for 26 hours altered choline uptake and metabolism, resulting in significant dose-dependent increases in the incidence and severity of malformations.^25;^ ^26^ The malformations included NTDs, craniofacial hypoplasia, caudal dysgenesis, and abnormal circulation. The average amount of embryonic protein was decreased in embryos exposed to 375 µM dimethylaminoethanol or higher.

### Humans

There are no studies in the literature on the developmental or reproductive toxicity of dimethylaminoethanol in humans. Decreases in choline are associated with NTDs in humans; however, the data are somewhat inconsistent.^30-32^ Dimethylaminoethanol is not recommended for use during pregnancy or lactation.^9;^ ^13^

## General Toxicity

### Experimental Animals

Reported oral LD_50_ (lethal dose for 50% of exposed animals) values for rats range from 2,000 to 6,000 mg/kg (22.44 to 67.31 mmol/kg) dimethylaminoethanol.^24;^ ^33^

Rats orally exposed to 890, 1,250, or 1,800 mg/kg/day dimethylaminoethanol for 14 days exhibited signs of toxicity early in the dosing period at the mid and high doses.^34^ Signs of toxicity included sluggishness, discharge around the eyes and nose, kyphosis, and prostration; however, these abated by days 2 to 5 in surviving animals. Observations at necropsy included red, mottled lungs, dark fluid in the stomach and intestine, and reddened stomach.

Exposure to dimethylaminoethanol via inhalation has been demonstrated to induce toxicity and mortality in rats. Exposure concentration-related mortality was observed in rats exposed to 1,668, 2,408, or 3,311 ppm dimethylaminoethanol for 4 hours and observed for 14 days.^35^ Rats from all exposure groups showed signs of toxicity including lacrimation, nasal discharge, respiratory difficulties, decreased motor activity, and weight loss.

Exposure of F344 rats to 98, 288, or 586 ppm dimethylaminoethanol via inhalation, 6 hours/day over 11 days (nine exposures total), caused 100% mortality at 586 ppm and some mortality at 288 ppm.^35^ Histologic lesions in the 288 and 98 ppm groups were observed primarily in the upper respiratory tract and in the eyes (288 ppm only). In a related study, F344 rats exposed to 8, 24, or 76 ppm dimethylaminoethanol via inhalation for 6 hours/day, 5 days/week for 13 weeks were observed with corneal opacity and alterations in nasal tissue at 24 and 76 ppm.^35^

Dimethylaminoethanol did not induce genotoxicity when evaluated in the Salmonella typhimurium assay, Drosophila melanogaster sex-linked recessive lethal assay, sister chromatid exchange assays, or hypoxanthine-guanine phosphoribosyl transferase forward gene mutation tests.^9;^ ^36-40^ There were no significant increases in micronucleated erythrocytes in Swiss-Webster mice exposed to 270 to 860 mg/kg dimethylaminoethanol.^40^

### Humans

No serious side effects were reported in humans treated orally with up to 1,200 mg dimethylaminoethanol/day (13.46 mmol/day).^41^

Oral administration of 10 to 20 mg (0.042 to 0.084 mmol) dimethylaminoethanol tartrate to humans caused mild mental stimulation.^24^ Doses of 20 mg/day (0.084 mmol) gradually increased muscle tone and the frequency of convulsions in more susceptible individuals. Larger doses (unspecified) induced insomnia, muscle tenseness, and sporadic muscle twitches.

Humans treated with dimethylaminoethanol to relieve tardive dyskinesia exhibited severe cholinergic side effects, including nasal and oral secretion, dyspnea, and respiratory failure.^42;^ ^43^ A meta-analysis of randomized controlled trials of dimethylaminoethanol indicated that not only was it no more effective at treating tardive dyskinesia than placebo, but treatment with dimethylaminoethanol was also associated with a significantly increased risk of adverse outcomes.^44;^ ^45^

## Genetic Toxicity

No studies on the genetic toxicity of dimethylaminoethanol were found in the published literature.

## Study Rationale

Dimethylaminoethanol was nominated by the National Institute of Environmental Health Sciences (NIEHS) for toxicological characterization due to the potential for widespread human exposure through its use in industrial and consumer products. Dimethylaminoethanol is structurally similar to choline, an essential nutrient, and might affect choline uptake and synthesis in the body. Given the limited literature indicating that dimethylaminoethanol may be a teratogen and reproductive toxicant, and given the possibility for widespread exposure to the salt form of dimethylaminoethanol (dimethylaminoethanol bitartrate) as a dietary supplement in women of childbearing age, NTP conducted prenatal developmental toxicity studies to assess the effects of oral dimethylaminoethanol bitartrate administration in pregnant rats and on fetal development.