# Appendix D Supplemental Files

The following supplemental files are available at [underlined: https://dx.doi.org/10.22427/NTP-DATA-DART-04].

## D.1 Prenatal Developmental Toxicity Dose Range-finding Study – Rats

I01 – Animal Removal Summary

I03 – Growth Curve

I04 – Mean Body Weights and Survival

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I06 – Mean Feed Consumption

PA46 – Gross Pathology Summary

R09 – Uterine Content Summary

R10 – Fetal Defects

R12 – Placental Findings

## D.2 Prenatal Developmental Toxicity Dose Range-finding Individual Animal Data – Rats

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Gross Pathology Data

Individual Animal Removal Reasons

Individual Animal Teratology Dam Data

Individual Animal Teratology Fetal Weight Data

Individual Animal Teratology Implant Data

## D.3 Prenatal Developmental Toxicity Study – Rats

I01 – Animal Removal Summary

I03 – Growth Curve

I04 – Mean Body Weights and Survival

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I06 – Mean Feed Consumption

PA06 – Organ Weights Summary

PA46 – Gross Pathology Summary

R09 – Uterine Content Summary

R10 – Fetal Defects

R11 – Fetal Defect Summary

R12 – Placental Findings

R13 – Fetal Defect Cross Reference Summary

## D.4 Prenatal Developmental Toxicity Individual Animal Data – Rats

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Gross Pathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons

Individual Animal Teratology Dam Data

Individual Animal Teratology Implant Data

Individual Animal Teratology Implant Findings Data