# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NIH-07 Rat and Mouse Ration

Table B-1 Ingredients of NIH-07 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground #2 Yellow Shelled Corn | 24.25
Ground Hard Winter Wheat | 23.00
Soybean Meal (49% protein) | 12.00
Wheat Middlings | 10.00
Fish Meal (60% protein) | 10.00
Dried Skim Milk | 5.00
Alfalfa Meal (Dehydrated, 17% Protein) | 4.00
Corn Gluten Meal (60% Protein) | 3.00
Soy Oil | 2.50
Dried Brewer’s Yeast | 2.00
Dry Molasses | 1.50
Dicalcium Phosphate | 1.25
Ground Limestone | 0.50
Salt | 0.50
Vitamin Premix^a^ | 0.25
Mineral Premix^b^ | 0.15
Choline Chloride (70% Choline) | 0.10

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NIH-07 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 5,500,000 IU | Stabilized vitamin A palmitate or acetate
D_3_ | 4,600,000 IU | D-activated animal sterol
K | 2.8 g | Dimethylpyrimidinol bisulfite
d-α-Tocopheryl Acetate | 20.0 g | –
Niacin | 30.0 g | –
Folic Acid | 2.2 g | –
d-Pantothenic Acid | 18.0 g | d-Calcium pantothenate
Riboflavin | 3.4 g | –
Thiamine | 10.0 g | Thiamine mononitrate
B_12_ | 45,400.0 µg | –
Pyridoxine | 5.9 g | Pyridoxine hydrochloride
Biotin | 140.0 mg | d-Biotin
Minerals
Iron | 120.0 g | Iron sulfate
Manganese | 60.0 g | Manganous oxide
Zinc | 16.0 g | Zinc oxide
Copper | 4.0 g | Copper sulfate
Iodine | 1.4 g | Calcium iodate
Cobalt | 0.4 g | Cobalt carbonate

^a^ Per ton (2,000 lb.) of finished product.

Table B-3 Nutrient Composition of NIH-07 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 23.25 ± 0.636 | 22.8–23.7 | 2
Crude Fat (% by Weight) | 5.75 ± 0.071 | 5.7–5.8 | 2
Crude Fiber (% by Weight) | 3.325 ± 0.092 | 3.26–3.39 | 2
Ash (% by Weight) | 6.36 ± 0.240 | 6.19–6.53 | 2
Amino Acids (% of Total Diet)
Arginine | 1.375 ± 0.065 | 1.30–1.49 | 8
Cysteine | 0.321 ± 0.035 | 0.274–0.372 | 8
Glycine | 1.145 ± 0.077 | 1.06–1.31 | 8
Histidine | 0.516 ± 0.023 | 0.497–0.553 | 8
Isoleucine | 0.982 ± 0.025 | 0.952–1.03 | 8
Leucine | 1.996 ± 0.054 | 1.93–2.08 | 8
Lysine | 1.261 ± 0.032 | 1.22–1.32 | 8
Methionine | 0.487 ± 0.015 | 0.468–0.515 | 8
Phenylalanine | 1.091 ± 0.020 | 1.07–1.12 | 8
Threonine | 0.919 ± 0.032 | 0.883–0.961 | 8
Tryptophan | 0.280 ± 0.022 | 0.266–0.326 | 8
Tyrosine | 0.855 ± 0.039 | 0.785–0.894 | 8
Valine | 1.134 ± 0.0245 | 1.11–1.17 | 8
Essential Fatty Acids (% of Total Diet)
Linoleic | 2.33 ± 0.211 | 2.04–2.59 | 8
Linolenic | 0.25 ± 0.028 | 0.217–0.296 | 8
Vitamins
Vitamin A (IU/kg) | 5,950 ± 66.5 | 5,480–6,420 | 2
α-Tocopherol (ppm) | 48.07 ± 4.38 | 40.3–52.73 | 8
Thiamine (ppm)^b^ | 11.3 ± 1.13 | 10.5–12.1 | 2
Riboflavin (ppm) | 14.3 ± 3.58 | 10.0–19.8 | 8
Niacin (ppm) | 99.4 ± 9.10 | 87.0–112 | 8
Pantothenic Acid (ppm) | 45.6 ± 3.13 | 40.4–51.1 | 8
Pyridoxine (ppm)^b^ | 12.33 ± 2.25 | 9.63–15.6 | 8
Folic Acid (ppm) | 2.47 ± 0.550 | 1.68–3.09 | 8
Biotin (ppm) | 0.342 ± 0.125 | 0.25–0.64 | 8
Vitamin B12 (ppb) | 50.21 ± 7.47 | 41.8–61.6 | 8
Choline (ppm)^b^ | 1,776 ± 197 | 1,570–2,200 | 8
Minerals
Calcium (%) | 1.190 ± 0.028 | 1.17–1.21 | 2
Phosphorus (%) | 0.978 ± 0.046 | 0.945–1.01 | 2
Potassium (%) | 0.829 ± 0.036 | 0.77–0.88 | 8
Chloride (%) | 0.625 ± 0.102 | 0.441–0.8 | 8
Sodium (%) | 0.368 ± 0.047 | 0.318–0.469 | 8
Magnesium (%) | 0.183 ± 0.009 | 0.170–0.194 | 8
Iron (ppm) | 376.3 ± 52.5 | 276–455 | 8
Manganese (ppm) | 91.03 ± 7.93 | 80.7–104 | 8
Zinc (ppm) | 64.07 ± 11.32 | 52.4–89.2 | 8
Copper (ppm) | 14.11 ± 2.91 | 11.9–21.1 | 8
Iodine (ppm) | 1.71 ± 0.886 | 0.54–3.45 | 8
Chromium (ppm) | 3.96 ± 0.033 | 3.91–4.00 | 8
Cobalt (ppm) | 0.53 ± 0.293 | 0.01–0.963 | 8

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table B-4 Contaminant Levels in NIH-07 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.368 ± 0.038 | 0.341–0.395 | 2
Cadmium (ppm) | 0.097 ± 0.010 | 0.09–0.104 | 2
Lead (ppm) | 0.074 ± 0.003 | 0.072–0.076 | 2
Mercury (ppm) | <0.02 | – | 2
Selenium (ppm) | 0.519 ± 0.092 | 0.454–0.584 | 2
Aflatoxins (ppb) | <5.00 | – | 2
Nitrate Nitrogen (ppm)^c^ | 25.05 ± 3.041 | 22.9–27.2 | 2
Nitrite Nitrogen (ppm)^c^ | <0.61 | – | 2
BHA (ppm)^d^ | <1.0 | – | 2
BHT (ppm)^d^ | <1.0 | – | 2
Aerobic Plate Count (CFU/g) | 10 | – | 2
Coliform (MPN/g) | 3.0 | – | 2
Escherichia coli (MPN/g) | <3 | – | 2
Salmonella (MPN/g) | Negative | – | 2
Total Nitrosoamines (ppb)^e^ | 5.1 ± 7.1 | 0–10.1 | 2
N-Nitrosodimethylamine (ppb)^e^ | 1.2 ± 1.6 | 0–2.3 | 2
N-Nitrosopyrrolidine (ppb)^e^ | 3.9 ± 5.5 | 0–7.8 | 2
Pesticides (ppm)
α-BHC | <0.01 | – | 2
β-BHC | <0.02 | – | 2
γ-BHC | <0.01 | – | 2
δ-BHC | <0.01 | – | 2
Heptachlor | <0.01 | – | 2
Aldrin | <0.01 | – | 2
Heptachlor Epoxide | <0.01 | – | 2
DDE | <0.01 | – | 2
DDD | <0.01 | – | 2
DDT | <0.01 | – | 2
HCB | <0.01 | – | 2
Mirex | <0.01 | – | 2
Methoxychlor | <0.05 | – | 2
Dieldrin | <0.01 | – | 2
Endrin | <0.01 | – | 2
Telodrin | <0.01 | – | 2
Chlordane | <0.05 | – | 2
Toxaphene | <0.10 | – | 2
Estimated PCBs | <0.20 | – | 2
Ronnel | <0.01 | – | 2
Ethion | <0.02 | – | 2
Trithion | <0.05 | – | 2
Diazinon | <0.10 | – | 2
Methyl Chlorpyrifos | 0.051 ± 0.02 | 0.037–0.065 | 2
Methyl Parathion | <0.02 | – | 2
Ethyl Parathion | <0.02 | – | 2
Malathion | 0.022 ± 0.003 | 0.02–0.024 | 2
Endosulfan I | <0.01 | – | 2
Endosulfan II | <0.01 | – | 2
Endosulfan Sulfate | <0.03 | – | 2

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All samples were irradiated.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.