# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 Dimethylaminoethanol Bitartrate

Dimethylaminoethanol bitartrate was obtained from Bayville Chemical Supply Company, Inc. (Deer Park, NY) in one lot (159AK) that was used in the dose range-finding and prenatal developmental toxicity studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) for the study laboratory at Southern Research (Birmingham, AL). Reports on analyses performed in support of the dimethylaminoethanol bitartrate studies are on file at the National Institute of Environmental Health Sciences.

Lot 159AK of the chemical, a white crystalline powder, was identified as dimethylaminoethanol bitartrate using Fourier transform infrared (FTIR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy. The exact mass for dimethylaminoethanol and tartaric acid was determined using ultra high-performance liquid chromatography (UHPLC) with time-of-flight mass spectrometry (TOF-MS) detection. In addition, the melting point of the bulk chemical was determined. All spectra were consistent with the structure and literature spectra^82;^ ^83^ of dimethylaminoethanol bitartrate. UHPLC/TOF-MS results measured values within 3.9 ppm or less of the theoretical mass values for dimethylaminoethanol and tartaric acid. The melting point^84^ was in good agreement with literature values. Representative FTIR and proton and carbon-13 NMR spectra are presented in Figure A-1, Figure A-2 and Figure A-3, respectively.

The moisture content of lot 159AK was measured by a desorption type Karl Fischer analysis and by thermogravimetric analysis (TGA); these procedures were conducted by Robertson Microlit Laboratory (Ledgewood, NJ). The purity of lot 159AK was determined by Galbraith Laboratories, Inc. (Knoxville, TN) using elemental analyses and by the analytical chemistry laboratory initially using UHPLC/TOF-MS with a hydrophilic interaction liquid chromatography (HILIC) gradient in the positive mode for dimethylaminoethanol and the negative mode for tartaric acid and subsequently using gas chromatography (GC) with MS detection. The UHPLC/TOF-MS system included a 1290 Infinity chromatograph with TOF-MS detection (Agilent, Santa Clara, CA) and a Waters Acquity^®^ UPLC BEH Amide (2.1 mm × 50 mm, 1.7 µM particle size) column (Waters Corporation, Milford, MA). The mobile phases consisted of (A) 10 mM ammonium acetate (pH 6.8) and (B) acetonitrile, programmed with a HILIC gradient of 5% A for 2 minutes, then to 95% A in 5 minutes, held for 0.5 minutes, reversed to 5% A in 2 minutes, and then held at 5% A for 2.5 minutes; the flow rate was 0.5 mL/minute. Assays for volatile organic impurities in the bulk chemical were conducted by the analytical chemistry laboratory using two GC systems with flame ionization detection (FID).

The Karl Fischer desorption analysis indicated approximately 12% water and TGA results indicated an estimated maximum water value not greater than 3.5%, calculated from the mass lost in the temperature range matching the boiling point of water. Elemental analyses for carbon, hydrogen, nitrogen, and oxygen were consistent with the structural composition of dimethylaminoethanol bitartrate and theoretical values. UHPLC/TOF-MS indicated one major peak accounting for greater than 99.9% of the total peak area relative to either the dimethylaminoethanol or tartaric acid peak. GC/MS using system A (Table A-1) indicated one major peak accounting for 100% of the total peak area; the spectrum was consistent with a library reference spectrum.^51^ A residual solvent screening assay using GC/FID by system B tentatively identified the presence of ethanol, chloroform, pyridine, and N,N-dimethylformamide. A second quantitative analysis using GC/FID by system C confirmed only the presence of one residual solvent, ethanol at 0.325%; the other analytes were not quantified above their corresponding limits of quantitation (~0.05 to 0.1%). The overall purity of lot 159AK was determined to be 96% or greater.

Stability studies of lot 159AK were conducted using the HILIC gradient UHPLC/TOF-MS system described above for the bulk chemical purity assessment. Results indicated that both dimethylaminoethanol and the counterion tartaric acid were stable in the bulk chemical for at least 14 days when stored in amber glass vials sealed with Teflon^®^-lined caps at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature in sealed glass bottles. Reanalyses of the bulk chemical were performed prior to the dose range-finding study and after the prenatal developmental toxicity study using FTIR spectroscopy (dose range-finding study only) and GC/FID by system D—no degradation of the bulk chemical was detected.

### A.1.2 Sterile Water for Irrigation, USP

The sterile water vehicle was obtained from Baxter Healthcare Corporation (Cleveland, MS) in two lots (G105999 and G110783). Lot G10599 was used in the dose range-finding study, and lot G110783 was used in the prenatal developmental toxicity study.

## A.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared once for each study by mixing dimethylaminoethanol bitartrate with sterile water to give the required concentrations (Table A-2). The dose formulations were stored at room temperature in sealed amber glass bottles for up to 42 days.

The analytical chemistry laboratory performed syringeability studies of a 300 mg/mL formulation using a 22-gauge gavage needle and syringe and stability studies of a 10 mg/mL formulation using GC/FID by system D (Table A-1). Syringeability was confirmed and stability was confirmed for at least 42 days for dimethylaminoethanol for dose formulations stored in sealed clear glass bottles both at refrigerated and room temperatures and for 3 hours under simulated animal room conditions.

Additional stability studies of formulations of dimethylaminoethanol bitartrate in sterile water were performed to monitor the relative stability of the tartaric acid counterion and the pH of the formulations. Two formulations (25.0 and 22.5 mg/mL) of dimethylaminoethanol bitartrate in sterile water were prepared for direct comparison to standards of tartaric acid at concentrations equivalent to those present in the formulations. After diluting into the range of a validated analytical method, a 300 mg/mL formulation was also analyzed using HPLC. The HPLC system included a Waters Alliance 2695 instrument (Waters Corporation) with a SIELC Primesep™ D 150 mm × 4.6 mm, 5 µM particle size column (SIELC Technologies, Wheeling, IL). The mobile phases were: (A) deionized water (adjusted to pH 2.2 with H_3_PO_4_), (B) acetonitrile, and (C) 100 mM NaH_2_PO_4_ in deionized water (adjusted to pH 2.7 with H_3_PO_4_). The isocratic gradient was 30% A, 10% B, and 60% C; ultraviolet detection was performed at 210 nm; and flow rate was 1.0 mL/minute. Formulations were determined to have a stable tartaric acid concentration for at least 42 days. The pH of the formulations across the concentration range 2.5 to 300 mg/mL was between 3.4 and 3.6; based on analysis of the 10 mg/mL formulation, the pH of the formulation did not change over the period of 42 days when stored at either refrigerated or room temperatures.

RTI conducted periodic analyses of the dose formulations of dimethylaminoethanol bitartrate using GC/FID by system D. During the dose range-finding study, the dose formulations were analyzed once; all three of the dose formulations were within 10% of the target concentrations (Table A-3). Animal room samples of these dose formulations were also analyzed, and all three were within 10% of the target concentrations. During the prenatal developmental toxicity study, the dose formulations were analyzed once; all three dose formulations analyzed were used and all three animal room samples were within 10% of the target concentrations (Table A-4).

Table A-1 Gas Chromatography Systems Used in the Gavage Studies of Dimethylaminoethanol Bitartrate^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Mass Spectrometry with Electron Impact Ionization (35 to 100 amu) | DB^TM^-WAX, 30 m× 0.32 mm, 0.5 µM film (J&W Scientific, Folsom, CA) | Helium at ~1.5 mL/minute | 60°C for 4 minutes, then increased by 20°C/minute to 240°C, held for 2 minutes
System B
Flame Ionization | DB^TM^-624, 30 m × 0.53 mm, 3.0 µM film (J&W Scientific) | Helium at ~4.5 mL/minute | 40°C for 20 minutes, then increased by 20°C/minute to 240°C, held for 20 minutes
System C
Flame Ionization | Rtx^®^-200, 30 m × 0.53 mm, 3.0 µM film thickness) (Restek, Bellefonte, PA) | Helium at ~4.5 mL/minute | 40°C for 20 minutes, then increased by 20°C/minute to 240°C, held for 20 minutes
System D
Flame Ionization | DB^TM^-WAX, 29 m × 0.53 mm, 1.0 µM film (J&W Scientific) | Helium at ~5 mL/minute | 80°C for 1 minute, then increased by 10°C/minute to 150°C, held for 7 or 12 minutes

^a^ The gas chromatographs and mass spectrometer were manufactured by Agilent Technologies, Inc. (Santa Clara, CA).

Table A-2 Preparation and Storage of Dose Formulations in the Gavage Studies of Dimethylaminoethanol Bitartrate in Rats

Dose Range-finding and Prenatal Developmental Toxicity Studies
Preparation
The dose formulations were prepared by weighing the appropriate amount of dimethylaminoethanol bitartrate into a small glass beaker, transferring the test article into a calibrated glass bottle with sterile water rinses, diluting to final volume with sterile water, and stirring for approximately 15 minutes. The dose formulations were prepared once for each study.
Chemical Lot Number
159AK
Maximum Storage Time
42 days
Storage Conditions
Stored in sealed amber glass bottles at room temperature
Study Laboratory
Southern Research (Birmingham, AL)

Table A-3 Results of Analyses of Dose Formulations Administered to Female Rats in the Dose Range-finding Gavage Study of Dimethylaminoethanol Bitartrate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
January 27, 2014 | January 28–29, 2014 | 50 | 50.9 | +2
| | 100 | 103 | +3
| | 200 | 203 | +2
| February 28, 2014^b^ | 50 | 50.0 | 0
| | 100 | 99.1 | −1
| | 200 | 207 | +4

^a^ Results of triplicate analyses. Dosing volume = 5 mL/kg; 50 mg/mL = 250 mg/kg, 100 mg/mL = 500 mg/kg, and 200 mg/mL = 1,000 mg/kg.

^b^ Animal room samples.

Table A-4 Results of Analyses of Dose Formulations Administered to Female Rats in the Prenatal Developmental Toxicity Gavage Study of Dimethylaminoethanol Bitartrate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
March 31, 2014 | April 2–4, 2014 | 50 | 53.6 | +7
| | 100 | 106 | +6
April 4, 2014 | | 200 | 220 | +10
| May 9, 2014^b^ | 50 | 52.3 | +5
| | 100 | 104 | +4
| | 200 | 219 | +10

^a^ Results of triplicate analyses. Dosing volume = 5 mL/kg; 50 mg/mL = 250 mg/kg, 100 mg/mL = 500 mg/kg, and 200 mg/mL = 1,000 mg/kg.

^b^ Animal room samples.

Figure A-1

Fourier Transform Infrared Absorption Spectrum of Dimethylaminoethanol Bitartrate

Figure A-2

Proton Nuclear Magnetic Resonance Spectrum of Dimethylaminoethanol Bitartrate

Figure A-3

Carbon-13 Nuclear Magnetic Resonance Spectrum of Dimethylaminoethanol Bitartrate