# References

1 World of Chemicals. Vinpocetine. India: Kimberlite Softwares Pvt. Ltd.; 2017. https://www.worldofchemicals.com/chemicals/chemical-properties/vinpocetine.html
2 Szabó L Kalaus G Szántay C Synthesis of vinca alkaloids and related compounds, XV^1)^ a new synthetic route to (+)-vincaminic and (+)-apovincaminic esters. Arch Pharm (Weinheim). 1983; 316:629–638. 10.1002/ardp.19833160709
3 Kuge Y Nakazawa H Kometani T Sugaya T Mochida K Tomioka S A facile one-pot synthesis of vinpocetine. Synth Commun. 1994; 24(6):759–766. 10.1080/00397919408011297
4 Linnea SA. Vinpocetine. Riazzino (TI), Switzerland: Linnea SA; 2017. [cited 2017 Jul 10]. https://www.linnea.ch/products.php?vinpocetine.
5 Mondelo FC, inventor. Process for the obtention of the ethyl ester of the apovincaminic acid. United States patent 4,870,178; 1989
6 Bereczki D Fekete I Vinpocetine for acute ischemic stroke. Stroke. 2008; 39(8):2404–2405. 10.1161/STROKEAHA.108.514174
7 Manconi EBFPF Binaghi F Pitzus F A double-blind clinical trial of vinpocetine in the treatment of cerebral insufficiency of vascular and degenerative origin. Curr Ther Res Clin Exp. 1986; 40(4):702–709.
8 Peruzza M DeJacobis M A double-blind placebo controlled evaluation of the efficacy and safety of vinpocetine in the treatment of patients with chronic vascular or degenerative senile cerebral dysfunction. Adv Ther. 1986; 3:201–209.
9 Thal LJ Salmon DP Lasker B Bower D Klauber MR The safety and lack of efficacy of vinpocetine in Alzheimer’s disease. J Am Geriatr Soc. 1989; 37(6):515–520. 10.1111/j.1532-5415.1989.tb05682.x 2715559
10 Feigin VL Doronin BM Popova TF Gribatcheva EV Tchervov DV Vinpocetine treatment in acute ischaemic stroke: A pilot single‐blind randomized clinical trial. Eur J Neurol. 2001; 8(1):81–85. 10.1046/j.1468-1331.2001.00181.x 11509086
11 Szatmári S, Whitehouse P. Vinpocetine for cognitive impairment and dementia. Cochrane Database Syst Rev. 2003; (3). 10.1002/14651858.CD003119
12 Ley BM Vinpocetine: Boost your brain power with periwinkle extract. Detriot Lakes, MN: B.L. Publications; 2000. p. 48.
13 South C. Clayton’s health facts: Vinpocetine. Boise, ID: Bodybuilding.com, LLC; 2007. https://web.archive.org/web/20130512171026/http:/www.bodybuilding.com/fun/southfacts_vin.htm
14 Gedeon Richter Ltd. Cavinton In: Chemical Works of Gedeon Richter Ltd. Budapest, Hungary: Gedeon Richter Ltd; 1984. p. 360–363.
15 Taiji H Kanzaki J Clinical study of vinpocetine in the treatment of vertigo. Jpn Pharmacol Ther. 1986; 14(577):89.
16 Truss MC Stief CG Ückert S Becker AJ Schultheiss D Machtens S Jonas U Initial clinical experience with the selective phosphodiesterase-I isoenzyme inhibitor vinpocetine in the treatment of urge incontinence and low compliance bladder. World J Urol. 2000; 18(6):439–443. 10.1007/PL00007088 11204266
17 Thorne Research Inc. Vinpocetine. Altern Med Rev. 2002; 7(3):240–243. 12126465
18 Sitges M Aldana BI Reed RC Effect of the anti-depressant sertraline, the novel anti-seizure drug vinpocetine and several conventional antiepileptic drugs on the epileptiform EEG activity induced by 4-aminopyridine. Neurochem Res. 2016; 41(6):1365–1374. 10.1007/s11064-016-1840-1 26830290
19 Crosby MG, Bennett RM, inventors. Compositions and methods for enhancing or treating female sexual response. United States patent 6,737,084 B2; 2004
20 Crosby MG, Bennett RM, inventors. Compositions and methods for enhancing and treating female sexual response. United States patent 8,128,972 B2; 2012
21 Luciano J, inventor. Dietary supplement and a method to enhance sleep and lucid dreaming. United States patent 8,092,840 B2; 2012
22 Misra AR, Gandhi NI, Bajaj MR, Shah BB, Samant RS, Rana H, inventors. Intranasal delivery to improve the performance of children suffering from dyslexia. World Intellectual Property Organization, International Bureau. International Publication Number WO 2011/055383 A2; 2011
23 Hendler SS Rorvik D Vinpocetine In: PDR for Nutritional Supplements. Montvale, NJ: Thomson Healthcare; 2001. p. 460.
24 Avula B Chittiboyina AG Sagi S Wang YH Wang M Khan IA Cohen PA Identification and quantification of vinpocetine and picamilon in dietary supplements sold in the United States. Drug Test Anal. 2016; 8(3-4):334–343. 10.1002/dta.1853 26426301
25 Federal Register. Request for comment on the status of vinpocetine. Washington, DC: U.S. Department of Health and Human Services, U.S. Food and Drug Administration; 2016. Docket No. FDA-2016-N-2523. Federal Register Vol. 81, No. 173.
26 Vereczkey L Pharmacokinetics and metabolism of vincamine and related compounds. Eur J Drug Metab Pharmacokinet. 1985; 10(2):89–103. 10.1007/BF03189702 3899662
27 Xia H-M Su L-N Guo J-W Liu G-M Pang Z-Q Jiang X-G Chen J Determination of vinpocetine and its primary metabolite, apovincaminic acid, in rat plasma by liquid chromatography–tandem mass spectrometry. J Chromatogr B Analyt Technol Biomed Life Sci. 2010; 878(22):1959–1966. 10.1016/j.jchromb.2010.05.029 20561830
28 Sozański T Magdalan J Trocha M Szumny A Merwid-Ląd A Słupski W Karaźniewicz-Łada M Kiełbowicz G Ksiądzyna D Szeląg A Omeprazole does not change the oral bioavailability or pharmacokinetics of vinpocetine in rats. Pharmacol Rep. 2011; 63(5):1258–1263. 10.1016/S1734-1140(11)70648-X 22180371
29 Vereczkey L Szporny L Metabolism of ethyl apovincaminate in the rat. Arzneimittelforschung. 1976; 26 10a:1933–1938. 1037219
30 Vereczkey L Szentirmay Z Szporny L Kinetic metabolism of vinpocetine in the rat. Arzneimittelforschung. 1979; 29(6):953–956. 582790
31 Chernoff N Rogers JM Hypoxia and the edema syndrome: Elucidation of a mechanism of teratogenesis. Birth Defects Res B Dev Reprod Toxicol. 2010; 89(4):300–303. 10.1002/bdrb.20258 20593454
32 Waidyanatha S Toy H South N Gibbs S Mutlu E Burback B McIntyre BS Catlin N Systemic exposure of vinpocetine in pregnant Sprague Dawley rats following repeated oral exposure: An investigation of fetal transfer. Toxicol Appl Pharmacol. 2018; 338:83–92. 10.1016/j.taap.2017.11.011 29155086
33 Nie S Fan X Peng Y Yang X Wang C Pan W In vitro and in vivo studies on the complexes of vinpocetine with hydroxypropyl-β-cyclodextrin. Arch Pharm Res. 2007; 30(8):991–1001. 10.1007/BF02993968 17879753
34 Ribeiro LSS Falcão AC Patrício JAB Ferreira DC Veiga FJB Cyclodextrin multicomponent complexation and controlled release delivery strategies to optimize the oral bioavailability of vinpocetine. J Pharm Sci. 2007; 96(8):2018–2028. 10.1002/jps.20294 17530626
35 Xu H He L Nie S Guan J Zhang X Yang X Pan W Optimized preparation of vinpocetine proliposomes by a novel method and in vivo evaluation of its pharmacokinetics in New Zealand rabbits. J Control Release. 2009; 140(1):61–68. 10.1016/j.jconrel.2009.07.014 19651165
36 Catlin N Waidyanatha S Mylchreest E Miller‐Pinsler L Cunny H Foster P Sutherland V McIntyre B Embryo‐fetal development studies with the dietary supplement vinpocetine in the rat and rabbit. Birth Defects Res. 2018; 110(10):883–896. 10.1002/bdr2.1207 29460393
37 Szakács T Veres Z Vereczkey L In vitro-in vivo correlation of the pharmacokinetics of vinpocetine. Pol J Pharmacol. 2001; 53(6):623–628. 11985336
38 Vereczkey L Czira G Tamás J Szentirmay Z Botár Z Szporny L Pharmacokinetics of vinpocetine in humans. Arzneimittelforschung. 1979; 29(6):957–960. 582791
39 Grandt R Beitinger H Schaltenbrand R Braun W Vinpocetine pharmacokinetics in elderly subjects. Arzneimittelforschung. 1989; 39(12):1599–1602. 2624613
40 Miskolczi P Kozma K Polgar M Vereczkey L Pharmacokinetics of vinpocetine and its main metabolite apovincaminic acid before and after the chronic oral administration of vinpocetine to humans. Eur J Drug Metab Pharmacokinet. 1990; 15(1):1–5. 10.1007/BF03190120 2384112
41 Lohmann A Dingler E Sommer W Schaffler K Wober W Schmidt W Bioavailability of vinpocetine and interference of the time of application with food intake. Arzneimittelforschung. 1992; 42(7):914–917. 1418055
42 Abd Elbary A Foda N El-Gazayerly O El Khatib M Reversed phase liquid chromatographic determination of vinpocetine in human plasma and its pharmacokinetic application. Anal Lett. 2002; 35(6):1041–1054. 10.1081/AL-120004554
43 Gulyás B Halldin C Sandell J Karlsson P Sóvágó J Kárpáti E Kiss B Vas A Cselényi Z Farde L PET studies on the brain uptake and regional distribution of [11C] vinpocetine in human subjects. Acta Neurol Scand. 2002; 106(6):325–332. 10.1034/j.1600-0404.2002.01302.x 12460136
44 Gulyás B Halldin C Sóvágó J Sandell J Cselényi Z Vas Á Kiss B Kárpáti E Farde L Drug distribution in man: A positron emission tomography study after oral administration of the labelled neuroprotective drug vinpocetine. Eur J Nucl Med Mol Imaging. 2002; 29(8):1031–1038. 10.1007/s00259-002-0823-4 12173017
45 Miskolczi P Vereczkey L Szalay L Göndöcs C Effect of age on the pharmacokinetics of vinpocetine (Cavinton) and apovincaminic acid. Eur J Clin Pharmacol. 1987; 33(2):185–189. 10.1007/BF00544565 3691609
46 Vlase L Bodiu B Leucuta SE Pharmacokinetics and comparative bioavailability of two vinpocetine tablet formulations in healthy volunteers by using the metabolite apovincaminic acid as pharmacokinetic parameter. Arzneimittelforschung. 2005; 55(11):664–668. 16366040
47 Cholnoky E Dömök LI Summary of safety tests of ethyl apovincaminate. Arzneimittelforschung. 1976; 26(10a):1938–1944. 1037220
48 Pálosi E Szporny L Effects of ethyl apovincaminate on the central nervous system. Arzneimittelforschung. 1976; 26(10a):1926–1929. 1037217
49 Ebi O Open-labeled phase III clinical trials with vinpocetine in Japan. Ther Hung. 1985; 33(1):41–49. 3915913
50 National Toxicology Program (NTP). DART-03: Growth and clinical finding tables (I), pathology tables (PA), developmental and reproductive tables (R) from NTP developmental and reproductive toxicity studies. Research Triangle Park, NC. 2019. 10.22427/NTP-DATA-002-03277-0000-0000-1
51 Chernoff N Setzer RW Miller DB Rosen MB Rogers JM Effects of chemically induced maternal toxicity on prenatal development in the rat. Teratology. 1990; 42(6):651–658. 10.1002/tera.1420420610 2087686
52 U.S. Environmental Protection Agency (USEPA). Guidelines for developmental toxicity risk assessment. Washington, DC: U.S. Environmental Protection Agency, Risk Assessment Forum; 1991. EPA Document No. EPA/600/FR-91/001.
53 Tyl RW Commentary on the role of maternal toxicity on developmental toxicity. Birth Defects Res B Dev Reprod Toxicol. 2012; 95(3):262–266. 10.1002/bdrb.21015 22706915
54 Organisation for Economic Co-operation and Development (OECD). OECD guideline for the testing of chemicals: Proposal for updating guideline 414: Prenatal developmental toxicity study. Paris, France: Organisation for Economic Co-operation and Development; 2001. https://ntp.niehs.nih.gov/iccvam/suppdocs/feddocs/oecd/oecd_gl414.pdf
55 Makris SL Solomon HM Clark R Shiota K Barbellion S Buschmann J Ema M Fujiwara M Grote K Hazelden KP Terminology of developmental abnormalities in common laboratory mammals (version 2). Congenit Anom (Kyoto). 2009; 49(3):123–246. 10.1111/j.1741-4520.2009.00239.x 20002907
56 Suckow M Stevens K Wilson R The laboratory rabbit, guinea pig, hamster, and other rodents. Amsterdam, Netherlands: Elsevier, Academic Press; 2012.
57 Suckow MA Weisbroth SH Franklin CL The laboratory rat. 2nd ed. Amsterdam, Netherlands: Elsevier; 2006.
58 Hayes AW Kruger CL Hayes’ principles and methods of toxicology. 6th ed. Boca Raton, FL: CRC Press; 2014. p. 1670–1672. 10.1201/b17359
59 Salewski E Färbemethode zum makroskopischen nachweis von implantationsstellen am uterus der ratte. Naunyn Schmiedebergs Arch Pharmacol. 1964; 247(4):367. 10.1007/BF02308461
60 Tyl RW Marr MC Developmental toxicity texting – methodology. Developmental and Reproductive Toxicology. 2nd ed. New York, NY: Taylor and Francis Group; 2006. p. 201–261.
61 Staples RE Detection of visceral alterations in mammalian fetuses. Teratology. 1974; 9:A37–A38.
62 Stuckhardt JL Poppe SM Fresh visceral examination of rat and rabbit fetuses used in teratogenicity testing. Teratog Carcinog Mutagen. 1984; 4(2):181–188. 10.1002/tcm.1770040203 6145223
63 Thompson RF Chapter 4: Basic neuroanatomy. Foundations of Physiological Psychology. New York, NY: Harper and Row Publishers; 1967. p. 79–82.
64 Marr MC Price CJ Myers CB Morrissey RE Developmental stages of the CD®(Sprague‐Dawley) rat skeleton after maternal exposure to ethylene glycol. Teratology. 1992; 46(2):169–181. 10.1002/tera.1420460210 1440420
65 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
66 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27:103–117. 10.2307/2528930 5547548
67 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28:519–531. 10.2307/2556164 5037867
68 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33:386–389. 10.2307/2529789 884197
69 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42:183–186. 10.2307/2531254 3719054
70 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
71 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. 10.2307/2333011
72 Dixon WJ Massey FJ Jr Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill Book Company, Inc; 1957. p. 276–278, 412.
73 Hsu JC The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168.
74 Armitage P Tests for linear trends in proportions and frequencies. Biometrics. 1955; 11(3):375–386. 10.2307/3001775
75 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
76 Zorrilla EP. Multiparous species present problems (and possibilities) to developmentalists. Dev Psychobiol. 1997; 30(2):141-150. 10.1002/(SICI)1098-2302(199703)30:2%3C141::AID-DEV5%3E3.0.CO;2-Q
77 Pendergast JF, Gange SJ, Lindstrom MJ. Correlated binary data In: Armitage P, Colton T, editors. Encyclopedia of Biostatistics. Hoboken, NJ: John Wiley; 2005. 10.1002/0470011815.b2a10018
78 Li B Lingsma HF Steyerberg EW Lesaffre E Logistic random effects regression models: A comparison of statistical packages for binary and ordinal outcomes. BMC Med Res Methodol. 2011; 11(1):77. 10.1186/1471-2288-11-77 21605357
79 Scott WJ Jr Resnick E Hummler H Clozel JP Bürgin H Cardiovascular alterations in rat fetuses exposed to calcium channel blockers. Reprod Toxicol. 1997; 11(2-3):207–214. 10.1016/S0890-6238(97)00008-7 9100294
80 DeSesso JM Comparative features of vertebrate embryology. Developmental and Reproductive Toxicology: A Practical Approach. Boca Raton, FL: CRC Press; 2006. p. 147–197.
81 Roguin N Du Z-D Barak M Nasser N Hershkowitz S Milgram E High prevalence of muscular ventricular septal defect in neonates. J Am Coll Cardiol. 1995; 26(6):1545–1548. 10.1016/0735-1097(95)00358-4 7594083
82 Solomon HM, Wier PJ, Fish CJ, Hart TK, Johnson CM, Posobiec LM, Gowan CC, Maleeff BE, Kerns WD. Spontaneous and induced alterations in the cardiac membranous ventricular septum of fetal, weanling, and adult rats. Teratology. 1997; 55(3):185-194. 10.1002/(SICI)1096-9926(199703)55:3%3C185::AID-TERA3%3E3.0.CO;2-1
83 Du Z-D Roguin N Wu X-J Spontaneous closure of muscular ventricular septal defect identified by echocardiography in neonates. Cardiol Young. 1998; 8(4):500–505. 10.1017/S1047951100007174 9855105
84 Paladini D Palmieri S Lamberti A Teodoro A Martinelli P Nappi C Characterization and natural history of ventricular septal defects in the fetus. Ultrasound Obstet Gynecol. 2000; 16(2):118–122. 10.1046/j.1469-0705.2000.00202.x 11117079
85 Hoffman JIE Kaplan S The incidence of congenital heart disease. J Am Coll Cardiol. 2002; 39(12):1890–1900. 10.1016/S0735-1097(02)01886-7 12084585
86 Fleeman TL Cappon GD Hurtt ME Postnatal closure of membranous ventricular septal defects in Sprague‐Dawley rat pups after maternal exposure with trimethadione. Birth Defects Res B Dev Reprod Toxicol. 2004; 71(3):185–190. 10.1002/bdrb.20011 15282739
87 Branch S, Rogers JM, Brownie CF, Chernoff N. Supernumerary lumbar rib: Manifestation of basic alteration in embryonic development of ribs. J Appl Toxicol. 1996; 16(2):115-119. 10.1002/(SICI)1099-1263(199603)16:2%3C115::AID-JAT309%3E3.0.CO;2-H
88 Foulon O Girard H Pallen C Urtizberea M Repetto–Larsay M Blacker AM Induction of supernumerary ribs with sodium salicylate. Reprod Toxicol. 1999; 13(5):369–374. 10.1016/S0890-6238(99)00029-5 10560585
89 Rogers JM Francis BM Barbee BD Chernoff N Developmental toxicity of bromoxynil in mice and rats. Fundam Appl Toxicol. 1991; 17(3):442–447. 10.1016/0272-0590(91)90195-A 1794648
90 Narotsky MG Francis EZ Kavlock RJ Developmental toxicity and structure-activity relationships of aliphatic acids, including dose-response assessment of valproic acid in mice and rats. Fundam Appl Toxicol. 1994; 22(2):251–265. 10.1006/faat.1994.1029 8005377
91 Beyer PE Chernoff N The induction of supernumerary ribs in rodents: Role of the maternal stress. Teratog Carcinog Mutagen. 1986; 6(5):419–429. 10.1002/tcm.1770060508 2878507
92 Chernoff N Kavlock RJ Beyer PE Miller D The potential relationship of maternal toxicity, general stress, and fetal outcome. Teratog Carcinog Mutagen. 1987; 7(3):241–253. 10.1002/tcm.1770070306 2888204
93 Wickramaratne GA. The post‐natal fate of supernumerary ribs in rat teratogenicity studies. J Appl Toxicol. 1988; 8(2):91–94. 10.1002/jat.2550080205 3379236
94 Chernoff N Rogers JM Turner CI Francis BM Significance of supernumerary ribs in rodent developmental toxicity studies: Postnatal persistence in rats and mice. Fundam Appl Toxicol. 1991; 17(3):448–453. 10.1016/0272-0590(91)90196-B 1794649
95 Foulon O, Jaussely C, Repetto M, Urtizberea M, Blacker AM. Postnatal evolution of supernumerary ribs in rats after a single administration of sodium salicylate. J Appl Toxicol. 2000; 20(3):205-209. 10.1002/(SICI)1099-1263(200005/06)20:3%3C205::AID-JAT635%3E3.0.CO;2-G
96 Khera KS Common fetal aberrations and their teratologic significance: A review. Fundam Appl Toxicol. 1981; 1(1):13–18. 10.1093/toxsci/1.1.13 6135638
97 Ujházy E Preinerová M Jozefík M Effects of cyclophosphamide on the prenatal development of the Swiss strain mice. Neoplasma. 1979; 26(5):529–537. 522926
98 Jeyaseelan N Singh S Forelimb malformation in rats caused by cyclophosphamide. Acta Orthop Scand. 1984; 55(6):643–646. 10.3109/17453678408992414 6524333
99 Matalon ST Ornoy A Lishner M Review of the potential effects of three commonly used antineoplastic and immunosuppressive drugs (cyclophosphamide, azathioprine, doxorubicin on the embryo and placenta). Reprod Toxicol. 2004; 18(2):219–230. 10.1016/j.reprotox.2003.10.014 15019720
100 Sadtler’s know-it-all IR spectral library. Retrieved from Bio-Rad Informatics “KnowItAll” System V.9.5 (No. 61,553). Hercules, CA: Bio-Rad; 2014.
101 The Merck Index. 14th ed. Whitehouse Station, NJ: Merck & Co., Inc.; 2006. p. 1719.
102 Hummel Surfactants Library. IR – Surfactants, Hummel – Wiley. Product Code – 465700, Spectra – 1,030. Bio-Rad Spectral Databases; 2018. http://www.knowitall.com/literature/english/databases/465700-Bio-Rad_IR_Surfactants_Hummel_Wiley_Spectral_Database_Specification_Sheet.pdf [Accessed: August 28, 2018]
103 Socrates G Infrared Characteristic Group Frequencies (ICGF). 2nd ed. New York, NY: John Wiley & Sons; 1994.