# Conclusions

Under the conditions of this rat prenatal study, there was clear evidence of developmental toxicity of vinpocetine in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats attributable to increased postimplantation loss and increased incidences of ventricular septum defects, thoracolumbar ribs (full), and incomplete ossification of the thoracic centrum in the absence of overt maternal toxicity.