# Discussion

Vinpocetine is a semisynthetic derivative of vincamine, an alkaloid extract derived from the periwinkle plant Vinca minor. Vinpocetine has been widely available as a pharmaceutical in Europe, Russia, China, and Japan for treatment of cerebrovascular and cognitive disorders.^6^ However, in the United States it is available as a dietary supplement with claims of cognitive enhancement.^7-11^ Interest in memory enhancement has shifted its use from a primarily older population to use by all ages, including women of childbearing potential (WOCBP). The one publication available for review^47^ provides insufficient information to effectively evaluate the safety of vinpocetine in a younger population that includes WOCBP.

The National Toxicology Program (NTP) conducted developmental studies with vinpocetine in the rat because of the possibility of widespread exposure to pregnant women and WOCBP and limited literature indicating that vinpocetine might not be safe for use during pregnancy. Additionally, a dose range-finding study in rabbits was included to see if effects occurred in a second species. The current Developmental and Reproductive Toxicity Technical Report presents the findings of the dose range-finding and prenatal developmental toxicity studies of vinpocetine in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and the dose range-finding study of vinpocetine in New Zealand White (Hra:NZW SPF) rabbits.

The prenatal toxicity study in rats provided clear evidence of developmental toxicity, with supportive evidence from the dose range-findings studies in rats and rabbits. In the dose range-finding study in rats, daily oral gavage exposure of 0, 20, 40, 80, 160, or 320 mg/kg resulted in lowered maternal body weight and body weight gains, decreased maternal feed consumption, clinical observations of abnormal vaginal discharge at ≥80 mg/kg, and significant embryo-fetal loss in all exposed groups.

Because of the increased incidences of fetal resorptions between the 40 and 80 mg/kg groups in the dose range-finding study, 60 mg/kg of vinpocetine was chosen as the high dose in the prenatal developmental toxicity study in rats. Maternal effects at 60 mg/kg were similar to those in the dose range-finding study: lowered maternal body weights and body weight gains (although, there was no significant effect when corrected for uterine weight); decreased feed consumption; and an increase in red vaginal discharge. These findings are consistent with a review of the industry studies published by Cholnoky and Dömök,^47^ in which oral gavage administration of vinpocetine to rats over the major period of organogenesis resulted in lowered maternal body weight gain at 50 mg/kg and uterine bleeding at 50 and 150 mg/kg.

In addition, in both the dose range-finding and prenatal developmental toxicity studies in rats, a dose-related increase in postimplantation loss occurred at doses ≥40 mg/kg. In the prenatal developmental toxicity study in rats, postimplantation loss of 83% occurred in dams administered 60 mg/kg. This increased postimplantation loss was a result of 12 dams with whole litter resorptions. Of the limited data in the literature (one paper reviewing 14 studies), high fetal mortality was noted following administration of 150 mg/kg vinpocetine to the dams in one study and complete litter resorptions were observed in 55% of the dams administered 135 mg/kg vinpocetine in another study.^47^

Evidence of teratogenicity in the rat prenatal developmental toxicity study consisted of exposure-related increased incidences in ventricular septum defects (VSDs). The incidences of VSDs were significantly increased between the 5 and 20 mg/kg dose groups, but not in the 60 mg/kg group. The lack of a dose-responsive increase in the number of VSDs at 60 mg/kg was likely a result of the significant postimplantation loss observed in this dose group (there were only 51 fetuses available for evaluation); however, the percent of affected fetuses was increased at both 20 and 60 mg/kg (3.1% and 3.9%) and was outside the NTP historical control range (0.0% to 0.5%) for Sprague Dawley rats.

VSDs are a malformation that arise from a disruption in the developmental processes that lead to partitioning of the ventricles and manifests as an opening in the interventricular septum (IVS). Development of the IVS is typically complete by GD 15 in rats, and consists of both muscular and membranous segments.^80^ VSDs can occur spontaneously, have been identified as the most common type of congenital heart disease in humans, and have been shown to close during postnatal development in both rats and humans.^81-85^ Membranous VSDs can also be induced in rats as a result of toxicant exposure.^82,86^ Administration of trimethadione on GD 9 and GD 10 resulted in a high incidence of membranous VSDs that were morphologically similar to spontaneously occurring VSDs, albeit larger in size.^82,86^ These toxicant-induced small membranous VSDs in rats have also been shown to close postnatally, indicative of a potential delay in cardiac development.^82,86^ The increased incidences of VSDs seen in the current studies with vinpocetine exposure could be indicative of a developmental delay; however, signs of delay (decreases in fetal weight and delays in ossification) were only observed in the 60 mg/kg group, and the incidences of VSDs were noted in the 5 and 20 mg/kg dose groups. Additionally, Fleeman et al.^86^ found no association between the occurrence of VSDs and decreased fetal weight, suggesting that VSDs are independent of overall fetal growth as measured by fetal weight. Therefore, the presence of VSDs at all doses in the current study were likely related to the administration of vinpocetine and not a secondary effect of delayed development.

Additional evidence of teratogenicity associated with vinpocetine exposure in the rats included significantly increased incidences in the formation of full supernumerary thoracolumbar ribs (SNRs). This malformation was present in 25.5% of the fetuses in the 60 mg/kg dose group where significant fetal mortality occurred (compared to 0.3% in the vehicle control group and 0.3% to 3.4% in the available historical control reports for fetuses from Sprague Dawley rats). The formation of supernumerary ribs in the thoracolumbar region is indicative of an alteration in early embryonic development of the axial skeleton^87^ and has been observed from exposure to a wide range of dissimilar chemicals in a dose-dependent manner, including sodium salicylate,^88^ bromoxynil phenol or bromoxynil octanoate,^89^ and valproic acid.^90^ Additionally, increased incidences of SNRs have previously been associated with maternal stress, although this effect appears to be species specific given that it has been demonstrated mainly in mice.^91,92^ Aside from the maternal effects associated with significant embryo-fetal loss, the doses of vinpocetine administered in the current studies did not produce signs of maternal stress or toxicity, indicating that the increased incidences of full SNRs in the current studies were likely related to vinpocetine exposure.

As incidences of full SNRs are indicators of developmental changes in axial skeleton development, they are generally not isolated events. Their formation has been significantly correlated with other findings in mice, such as the presence of an additional presacral vertebra.^31^ An increase in the incidences of greater than 26 presacral vertebrae was seen in the current rat studies in fetuses from dams exposed to 60 mg/kg vinpocetine. All of the fetuses with this variation also had incidences of full SNRs (bilateral or on the left only).

Incidences of short SNRs, or rudimentary ribs, were significantly increased in the fetuses of dams exposed to 20 and 60 mg/kg vinpocetine. However, increased incidences of short SNRs are a common background variation in this strain of rat, and their presence is transient and has been shown to diminish during the postnatal period in rats.^93-95^ In contrast, full SNRs have been shown to persist from birth into adulthood, as demonstrated by Foulon et al.^95^ who examined salicylate-induced full SNRs over time through radiography. Incidences of full SNRs in the lumbar region have also been reported in humans, where they have been associated with adverse outcomes such as pain in the lumbar region and increased incidences of lumbar vertebrae L4 and L5 degeneration.^31^

Exposure to vinpocetine during gestation resulted in fetal growth retardation in the rats demonstrated by significant increases in the percentage of fetuses with incomplete ossification of the thoracic centrum and decreased fetal weights. The thoracic centrum is the body, or centrum, of the thoracic vertebrae and is routinely ossified before birth. Aside from fetal weight, the degree of ossification of the main components of the axial skeleton and the extremities in the fetus are typical indicators of developmental status.^96^ Cyclophosphamide is an example of another toxicant for which prenatal exposure in mice and rats resulted in fetal resorptions, as well as growth retardation, delayed ossification, and skeletal malformations.^97-99^ Maternal stress and malnutrition, especially during the period of rapid fetal growth late in gestation, can also result in reduced fetal weight and incomplete skeletal ossification. That mode of action, however, is not likely for vinpocetine exposure in these studies, because the reduced maternal body weights and feed consumption seen in this study were a result of fetal loss and not loss of non-uterine body mass of the dams.

A dose range-finding study was also performed in rabbits to determine if the effects observed in rats would be observed in species other than rodents. In the dose range-finding study in rabbits, daily oral gavage exposure of 0, 25, 75, 150, or 300 mg/kg did not result in overt maternal toxicity. As was seen in the rats, the vinpocetine-exposed does displayed several effects related to embryo-fetal loss, including decreased body weights and feed consumption and clinical observations of abnormal vaginal discharge. Those effects, however, were mainly limited to the does in the 300 mg/kg group. Information available in the literature on fetal effects of vinpocetine administration during gestation in rabbits was limited to a paragraph in the Cholnoky and Dömök^47^ summary of safety tests. Although few details were reported, the authors noted that a small significant reduction in body weight gain in the high-dose group was observed (orally administered, 18 mg/kg) with no other evidence of maternal toxicity.

Similar to the rats, in the current rabbit study there was an increase in percent postimplantation loss; however, it was limited to the 300 mg/kg group and the magnitude of the response was less than in the rat, although significantly increased compared to the vehicle control group. Additionally, a decrease in fetal weight at 300 mg/kg was observed in both male and female rabbits.

The developmental toxicity of vinpocetine was notable in that related findings, including embryo-fetal lethality and decreased fetal weights, occurred in two species in the absence of overt maternal toxicity. The doses where these effects were significant were 60 mg/kg in the rat and 300 mg/kg in the rabbit. In a toxicokinetics study in pregnant rats, significant fetal transfer of vinpocetine occurred following repeat administration of vinpocetine (5 and 20 mg/kg) daily from GD 6 to GD 18.^32^ In this study, pooled fetal C_max_ and AUC values were ≥55% of dam values. Additionally, this study identified the rapid metabolism of vinpocetine to its main metabolite, apovincaminic acid, in the dam, with apovincaminic acid levels 2.7-fold higher (based on C_max_ and AUC) than vinpocetine in dam plasma. However, apovincaminic acid levels in the fetus were much lower than vinpocetine. Examination of the plasma levels of vinpocetine and apovincaminic acid in dosed rabbits on GD 19 revealed that both compounds were increased in a less than dose-proportional manner. In the limited comparison between the two species, dose-normalized vinpocetine levels in plasma at 1 and 2 hours after administration of the last dose were found to be 7- to 15-fold higher in the rats (5 and 20 mg/kg) compared to the rabbits (25 mg/kg). In contrast, the dose-normalized apovincaminic acid levels in rabbits were 19- to 75-fold higher than rats. These findings indicate a species difference in metabolism, with higher vinpocetine levels in the rat and higher apovincaminic acid levels in the rabbit, and offer a plausible explanation for the species difference observed in fetal mortality.^36^

For humans, the doses of vinpocetine recommended by the Physicians’ Desk Reference for Nutritional Supplements and the doses that are suggested on available product labels range from 5 to 60 mg/day.^23^ A comparison of exposure in rats at 5 mg/kg to suggested doses in humans (single 10 mg dose) suggested exposure multiples of ≤13.6 and ≤8.5 for C_max_ and AUC, respectively, based on blood levels between the two species.^32^ These dose comparisons suggest that exposure to vinpocetine in rats following a repeated 5 mg/kg dose (as conducted in the current studies) is similar to that following a single 10 mg dose in humans.

Exposure to vinpocetine during gestation in rats and rabbits resulted in evidence of developmental toxicity as exhibited by embryo-fetal death. Additional findings included reductions in fetal weight (rat and rabbit) and malformations and variations of the heart and skeleton in the rat.