# Results

## Data Availability

NTP evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-002-03277-0000-0000-1.^50^

## Dose Range-finding Study in Rats

### Maternal Findings

#### Viability and Clinical Observations

All rats survived until the end of the study (Table 3). Clinical observations of red or brown vaginal discharge occurred in all groups (4, 5, 7, 10, 10, and 9 dams in the 0, 20, 40, 80, 160, and 320 mg/kg groups, respectively; Appendix E^50^). Other observations included brown discoloration of the nares (1, 2, 8, and 10 dams in the 40, 80, 160 and 320 mg/kg groups, respectively) and piloerection in all dams administered 160 or 320 mg/kg, which occurred beginning on gestation day (GD) 7 through the end of the dosing period.

Table 3 Maternal Disposition of Rats in the Dose Range-finding Gavage Study of Vinpocetine

| 0 mg/kg | 20 mg/kg | 40 mg/kg | 80 mg/kg | 160 mg/kg | 320 mg/kg
Time-mated females | 10 | 10 | 10 | 10 | 10 | 10
Pregnant (on GD 21) | 8 | 10 | 8 | 10 | 10 | 9
Nonpregnant (on GD 21) | 2 | 0 | 2 | 0 | 0 | 1

GD = gestation day.

#### Body Weights and Feed Consumption

Dose-related decreases in mean maternal body weights and mean body weight gains were observed in groups administered 40 mg/kg or greater, relative to those of the vehicle controls, from GD 6 to GD 21 (Figure 4, Table 4. Maternal body weights were 28%, 31%, and 35% lower than those of vehicle controls in the 80, 160, and 320 mg/kg groups, respectively. When adjusted for gravid uterine weight (at necropsy), maternal body weights were 4.5%, 11%, and 14% lower than those of vehicle controls in the 80, 160, and 320 mg/kg groups, respectively and were associated with the embryo-fetal loss also observed in these groups. Daily mean body weights for dams in each dose group are available in Appendix E.^50^

Figure 4

Maternal Growth Curves for Pregnant Rats Administered Vinpocetine by Gavage in the Dose Range-finding Study

Information for statistical significance in maternal weights is provided in Table 4 and Appendix E.^50^

Table 4 Summary of Maternal Body Weight Gains of Rats in the Dose Range-finding Gavage Study of Vinpocetine^a^

Gestation Day Interval | 0 mg/kg | 20 mg/kg | 40 mg/kg | 80 mg/kg | 160 mg/kg | 320 mg/kg
6–21 | 137.1 ± 5.3** (8) | 134.5 ± 8.5 (10) | 109.1 ± 14.3* (8) | 34.3 ± 3.1** (10) | 24.8 ± 4.3** (10) | 9.3 ± 2.4** (9)
3–6 | 13.9 ± 3.4 (8) | 11.9 ± 0.8 (10) | 9.3 ± 1.9 (8) | 13.6 ± 2.3 (10) | 11.6 ± 1.7 (10) | 12.2 ± 1.7 (9)
6–9 | 14.6 ± 1.5** (8) | 13.8 ± 1.6 (10) | 5.2 ± 4.8* (8) | 2.1 ± 2.2** (10) | −10.2 ± 2.2** (10) | –21.6 ± 3.0** (9)
9–12 | 15.0 ± 1.2* (8) | 18.0 ± 1.0 (10) | 20.6 ± 3.6 (8) | 16.9 ± 2.3 (10) | 15.3 ± 1.9 (10) | 4.4 ± 2.6** (9)
12–15 | 19.0 ± 1.9** (8) | 18.8 ± 1.8 (10) | 16.1 ± 2.6 (8) | 6.2 ± 1.5** (10) | 8.0 ± 2.7** (10) | 8.3 ± 2.0** (9)
15–18 | 41.1 ± 1.4** (8) | 38.7 ± 2.8 (10) | 23.4 ± 6.7** (8) | 8.5 ± 1.3** (10) | 5.6 ± 1.3** (10) | 7.2 ± 2.2** (9)
18–21 | 47.4 ± 2.2** (8) | 45.2 ± 3.4 (10) | 43.8 ± 6.7 (8) | 0.6 ± 2.3** (10) | 6.0 ± 2.7** (10) | 11.0 ± 2.8** (9)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or by pairwise comparison (Williams or Dunnett test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Body weight gains for pregnant females are given in grams. Data are displayed as mean ± standard error (n).

Concomitant treatment-related, dose-dependent decreases in maternal feed consumption were observed with doses of 40 mg/kg or greater from GD 6 to GD 21 (Table 5) and were 8%, 19%, 28%, and 38% lower than that of the vehicle controls in the 40, 80, 160, and 320 mg/kg groups, respectively.

Table 5 Summary of Maternal Feed Consumption of Rats in the Dose Range-finding Gavage Study of Vinpocetine^a^

Gestation Day Interval | 0 mg/kg | 20 mg/kg | 40 mg/kg | 80 mg/kg | 160 mg/kg | 320 mg/kg
6–21 | 21.2 ± 0.4** (8) | 21.2 ± 0.6 (10) | 19.5 ± 0.8 (8) | 17.1 ± 0.4** (10) | 15.2 ± 0.5** (10) | 13.0 ± 0.4** (9)
3–6 | 18.9 ± 0.8 (8) | 19.0 ± 0.5 (10) | 18.5 ± 0.8 (8) | 18.8 ± 0.8 (10) | 18.7 ± 0.4 (10) | 18.9 ± 0.7 (9)
6–9 | 18.4 ± 0.7** (8) | 17.3 ± 0.6 (10) | 14.0 ± 1.0** (8) | 11.5 ± 0.3** (10) | 6.8 ± 0.5** (10) | 5.3 ± 0.7** (9)
9–12 | 20.8 ± 0.5** (8) | 20.4 ± 0.5 (10) | 18.8 ± 0.9 (8) | 18.1 ± 0.5** (10) | 15.7 ± 0.5** (10) | 11.7 ± 0.9** (9)
12–15 | 21.2 ± 0.5** (8) | 21.6 ± 0.6 (10) | 21.5 ± 1.0 (8) | 19.8 ± 0.4 (10) | 18.7 ± 0.8* (10) | 16.3 ± 0.6** (9)
15–18 | 22.5 ± 0.4** (8) | 23.8 ± 0.9 (10) | 21.0 ± 1.7 (8) | 19.7 ± 0.7 (10) | 18.4 ± 0.8** (10) | 16.1 ± 0.7** (9)
18–21 | 22.8 ± 0.5** (8) | 22.8 ± 0.8 (10) | 22.4 ± 1.5 (8) | 16.7 ± 0.7** (10) | 16.3 ± 0.6** (10) | 15.6 ± 0.4** (9)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Shirley or Dunn test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Feed consumption for pregnant females is given in grams/day. Data are displayed as mean ± standard error. Number of dams with feed consumption measured is given in parentheses.

#### Maternal and Litter Observations

At necropsy, no gross observations related to vinpocetine administration were observed.

There was an exposure-related effect on percent postimplantation loss as a result of increased early resorptions across all groups (Table 6). Although not statistically significant at 20 and 40 mg/kg, these values were greater than those of the vehicle controls. At doses of 80 mg/kg and above, dams exhibited total resorption of their litters, except for one dam in the 160 mg/kg group. Because of the increased postimplantation loss, the number of live fetuses per litter decreased in the 40 mg/kg group in comparison to the vehicle controls, and there were no live fetuses at doses of 80 mg/kg and above with the exception of the one litter in the 160 mg/kg group that contained 12 live fetuses. These findings were associated with reductions in mean gravid uterine weights (13.7%, 26.0%, 97.6%, 88.8%, and 96.8% less than the vehicle control group at 20, 40, 80, 160, and 320 mg/kg, respectively).

Table 6 Summary of Uterine Content Data for Rats in the Dose Range-finding Gavage Study of Vinpocetine

| 0 mg/kg | 20 mg/kg | | 40 mg/kg | 80 mg/kg | | 160 mg/kg | | 320 mg/kg
Pregnancy Summary
Mated females | 10 | 10 | | 10 | 10 | | 10 | | 10
Pregnant females | 8 | 10 | | 8 | 10 | | 10 | | 9
Pregnant females examined on GD 21^a^ | 8 | 10 | | 8 | 10 | | 10 | | 9
Corpora lutea per female^b^ | 15.63 ± 0.50 (8) | 16.20 ± 0.49 (10) | | 17.25 ± 1.08 (8) | 16.50 ± 0.70 (10) | | 17.00 ± 0.54 (10) | | 15.44 ± 0.50 (9)
Implantations^b^ per female | 14.38 ± 0.42 (8) | 14.10 ± 0.74 (10) | | 14.00 ± 0.65 (8) | 13.40 ± 1.1 (10) | | 14.50 ± 0.76 (10) | | 14.56 ± 0.73 (9)
Percent postimplantation loss^b^ | 5.30 ± 1.78** (8) | 18.41 ± 11.70 (10) | | 27.55 ± 12.35 (8) | 100.00 ± 0.00** (10) | | 90.77 ± 9.23** (10) | | 100.00 ± 0.00** (9)
Total resorptions per litter^b^ | 0.75 ± 0.25** (8) | 2.60 ± 1.65 (10) | | 3.88 ± 1.79 (8) | 13.40 ± 1.19** (10) | | 13.30 ± 1.56** (10) | | 14.56 ± 0.73** (9)
Early resorptions per litter^b^ | 0.75 ± 0.25** (8) | 2.60 ± 1.65 (10) | | 3.88 ± 1.79 (8) | 13.40 ± 1.19** (10) | | 13.30 ± 1.56** (10) | | 14.56 ± 0.73** (9)
Late resorptions per litter^b^ | 0.00 ± 0.00 (8) | 0.00 ± 0.00 (10) | | 0.00 ± 0.00 (8) | 0.00 ± 0.00 (10) | | 0.00 ± 0.00 (10) | | 0.00 ± 0.00 (9)
Dead fetuses per litter^b^ | 0.00 ± 0.00 (8) | 0.00 ± 0.00 (10) | | 0.00 ± 0.00 (8) | 0.00 ± 0.00 (10) | | 0.00 ± 0.00 (10) | | 0.00 ± 0.00 (9)
Number of early resorptions^c^ | 6 | 26 | | 31 | 134 | | 133 | | 131
Number of late resorptions | 0 | 0 | | 0 | 0 | | 0 | | 0
Number of whole litter resorptions^a^ | 0** | 1 | | 1 | 10** | | 9** | | 9**
Number of dead fetuses | 0 | 0 | | 0 | 0 | | 0 | | 0
Live Fetuses^b^
Number of live fetuses | 109 | 115 | | 81 | 0 | | 12 | | 0
Live fetuses per litter | 13.63 ± 0.53** (8) | 11.50 ± 1.78 (10) | | 10.13 ± 1.85 (8) | 0.00 ± 0.00** (10) | | 1.20 ± 1.20** (10) | | 0.00 ± 0.00** (9)
Live male fetuses per litter | 5.88 ± 0.55** (8) | 5.70 ± 0.96 (10) | | 6.13 ± 1.08 (8) | 0.00 ± 0.00** (10) | | 0.40 ± 0.40** (10) | | 0.00 ± 0.00** (9)
Live female fetuses per litter | 7.75 ± 0.73** (8) | 5.80 ± 1.04 (10) | | 4.00 ± 1.16* (8) | 0.00 ± 0.00** (10) | | 0.80 ± 0.80** (10) | | 0.00 ± 0.00** (9)
Percent live male fetuses per litter | 43.35 ± 4.01 (8) | 48.83 ± 4.82 (9) | | 64.60 ± 7.92 (7) | | | 33.33 (1)
Fetal Weight (g)^c^
Fetal body weight per litter | 5.18 ± 0.07 (8) | 5.26 ± 0.16 (9) | | 5.06 ± 0.16 (7) | –^d^ | | 4.98 (1) | | –^d^
Male fetal weight per litter | 5.33 ± 0.07 (8) | 5.41 ± 0.16 (9) | | 5.16 ± 0.16 (7) | | | 5.06 (1)
Female fetal weight per litter | 5.06 ± 0.07 (8) | 5.11 ± 0.14 (9) | | 4.92 ± 0.19 (6) | | | 4.95 (1)
Gravid Uterine Weight (g)^e^
Gravid uterine weight | 96.41 ± 3.22** (8) | 83.23 ± 11.81 (10) | | 71.35 ± 12.39* (8) | 2.35 ± 0.20** (10) | | 10.78 ± 8.21** (10) | | 3.09 ± 0.56** (9)
Terminal body weight | 383.2 ± 4.7** (8) | 376.2 ± 10.7 (10) | | 347.5 ± 13.9** (8) | 276.1 ± 3.4** (10) | | 266.3 ± 5.4** (10) | | 250.2 ± 5.3** (9)
Adjusted body weight | 286.83 ± 3.30** (8) | 292.96 ± 8.77 (10) | | 276.18 ± 4.45 (8) | 273.76 ± 3.31 (10) | | 255.53 ± 10.69** (10) | | 247.10 ± 5.39** (9)

Values are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to the end of the study.

GD = gestation day.

* Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column).

** p ≤ 0.01.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

^b^ Statistical analysis on number per litter performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Statistical analysis performed using a mixed-effects linear model with litter as a random effect.

^d^ No live fetuses in dose group.

^e^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests; adjusted body weight = terminal body weight minus gravid uterine weight.

No exposure-related effects were observed on fetal weight or fetal sex ratio in the 20 or 40 mg/kg groups; fetal weight and sex ratio could not be evaluated at 80, 160, or 320 mg/kg due to the presence of only one litter among these groups (Table 6).

### Fetal Findings

#### External

No external malformations or variations were attributed to vinpocetine exposure at 20, 40, 80, 160, or 320 mg/kg per day (Appendix E^50^). External findings in exposed fetuses were limited to a singular occurrence of subcutaneous hemorrhage in the 20 mg/kg group, which was therefore considered to be unrelated to vinpocetine exposure.

## Dose Selection Rationale for the Prenatal Development Toxicity Study in Rats

In the dose range-finding study, embryo-fetal loss occurred at all doses (20, 40, 80, 160, and 320 mg/kg per day), with a significant increase in the number of fetal resorptions compared to the control group observed between 40 and 80 mg/kg per day (28% and 100% postimplantation loss, respectively). In accordance with these findings, 60 mg/kg per day was chosen as the highest dose for the prenatal developmental toxicity study. To provide adequate dose spacing for evaluation of potential dose-response relationships and ideally to capture the no-observed-effect level (NOEL), approximately half log-dose intervals were used. The doses selected for the prenatal developmental toxicity study were 0, 5, 20, and 60 mg/kg per day.

## Prenatal Developmental Toxicity Study in Rats

### Maternal Findings

#### Viability and Clinical Observations

No animals were removed from the study prior to scheduled necropsy (Table 7). There were test article-related clinical observations at ≥20 mg/kg, which were limited to a dose-related increase in the incidence of red or brown vaginal discharge (6, 4, 13, and 17 dams in the 0, 5, 20, and 60 mg/kg groups, respectively; Appendix E^50^). Observations of abnormal vaginal discharge generally began on GD 13 and continued until GD 19. There were no treatment-related clinical observations in the 5 mg/kg animals.

Table 7 Maternal Disposition of Rats in the Prenatal Developmental Toxicity Gavage Study of Vinpocetine

| 0 mg/kg | 5 mg/kg | 20 mg/kg | 60 mg/kg
Time-mated Females | 25 | 25 | 25 | 25
Pregnant (on GD 21) | 21 | 20 | 22 | 20
Nonpregnant (on GD 21) | 4 | 5 | 3 | 5

GD = gestation day.

#### Body Weights and Feed Consumption

Significant decreases in mean maternal body weights and mean body weight gains during gestation occurred in the 60 mg/kg group (Figure 5; Table 8). Relative to the vehicle controls, administration of 60 mg/kg vinpocetine resulted in a 23% reduction in maternal body weight on GD 21 and a 61% reduction in maternal body weight gain from GD 6 to GD 21. The decrease in maternal weight was associated with lower gravid uterine weight. Mean adjusted body weight at necropsy (total minus gravid uterine weight) was not significantly affected with vinpocetine administration. The maternal body weight decreases in the 60 mg/kg group were associated with 83% postimplantation loss (compared to 3% in the vehicle control group), which included total litter resorptions in 12 dams and resulted in fewer live fetuses. There were no significant maternal body weight changes in the 5 or 20 mg/kg groups. Daily mean body weights for dams in each dose group are available in Appendix E.^50^

Figure 5

Maternal Growth Curves for Pregnant Rats Administered Vinpocetine by Gavage in the Prenatal Developmental Toxicity Study

Information for statistical significance in maternal weights is provided in Table 8 and Appendix E.^50^

Table 8 Summary of Maternal Body Weight Gains of Rats in the Prenatal Developmental Toxicity Gavage Study of Vinpocetine^a^

Gestation Day Interval | 0 mg/kg | 5 mg/kg | 20 mg/kg | 60 mg/kg
6–21 | 142.8 ± 3.4** (21)^b^ | 128.7 ± 7.4 (20) | 130.0 ± 5.1 (22) | 55.3 ± 7.9** (20)
3–6 | 13.7 ± 1.0 (21) | 13.1 ± 1.0 (20) | 13.5 ± 1.2 (22) | 14.5 ± 2.0 (20)
6–9 | 13.2 ± 0.7** (21) | 11.3 ± 0.8 (20) | 12.2 ± 0.9 (22) | 5.2 ± 1.0** (20)
9–12 | 16.0 ± 0.6 (21) | 15.4 ± 0.9 (20) | 16.0 ± 0.8 (22) | 13.4 ± 1.2 (20)
12–15 | 20.7 ± 0.8** (21) | 17.7 ± 1.3 (20) | 17.8 ± 0.8 (22) | 9.9 ± 1.7** (20)
15–18 | 40.8 ± 1.4** (21) | 38.1 ± 2.4 (20) | 37.0 ± 2.0 (22) | 15.4 ± 2.5** (20)
18–21 | 52.2 ± 1.7** (21) | 46.2 ± 3.3 (20) | 47.0 ± 2.4 (22) | 11.5 ± 4.5** (20)

** Statistically significant (p ≤ 0.01) trend (by the Jonckheere test) or pairwise comparison (by the Williams or Dunnett test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

^a^ Body weight gains for pregnant females are given in grams. Data are displayed as mean ± standard error.

^b^ Number of dams weighed is given in parentheses.

Treatment-related effects on feed consumption were limited to the 60 mg/kg/day group and consisted of a slight decrease in overall feed consumption from GD 6 to GD 21 in this dose group (9.5% lower than the vehicle control group; Table 9). Feed consumption in the 5 and 20 mg/kg/day dose groups was similar to that of the vehicle control group.

Table 9 Summary of Maternal Feed Consumption of Rats in the Prenatal Developmental Toxicity Gavage Study of Vinpocetine^a^

Gestation Day Interval | 0 mg/kg | 5 mg/kg | 20 mg/kg | 60 mg/kg
6–21 | 22.0 ± 0.3** (21) | 21.6 ± 0.4 (20) | 22.2 ± 0.3 (22) | 19.9 ± 0.4** (20)
3–6 | 19.6 ± 0.6 (16) | 19.5 ± 0.4 (17) | 19.8 ± 0.4 (18) | 20.4 ± 0.6 (16)
6–9 | 20.0 ± 0.4** (21) | 19.6 ± 0.3 (20) | 19.3 ± 0.3 (22) | 17.2 ± 0.4** (20)
9–12 | 20.7 ± 0.3* (21) | 20.1 ± 0.4 (20) | 20.9 ± 0.3 (22) | 18.8 ± 0.5** (20)
12–15 | 21.2 ± 0.3 (21) | 21.0 ± 0.5 (20) | 21.5 ± 0.4 (22) | 21.5 ± 0.6 (20)
15–18 | 23.5 ± 0.3 (21) | 23.3 ± 0.5 (20) | 24.7 ± 0.4 (22) | 21.7 ± 0.5* (20)
18–21 | 24.4 ± 0.4** (21) | 24.1 ± 0.6 (20) | 24.7 ± 0.4 (22) | 20.2 ± 0.7** (20)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Shirley or Dunn test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Feed consumption for pregnant females is given in grams/day. Data are displayed as mean ± standard error. Number of dams with feed consumption measured is given in parentheses.

#### Maternal and Litter Observations

There were no notable maternal necropsy findings. The number of pregnant females and the mean numbers of corpora lutea and implantation sites were similar across groups.

There was a significant effect on percent postimplantation loss in the 60 mg/kg group (83.1% compared to 3.3% in the vehicle control group) as a result of resorption of entire litters in 12 of the dams and increased incidences of resorptions in 7 of the dams (Table 10). Because of the increased postimplantation loss, there was a decrease in the number of live fetuses per litter in the 60 mg/kg group (2.6 compared to 14.0 in vehicle controls), which was associated with an 80% decrease in gravid uterine weight in this group. Mean percent postimplantation loss for the 5 and 20 mg/kg groups (10.7% and 11.1%, respectively) was higher than in the concurrent vehicle control group (3.3%) and higher than NTP historical control values (2.9% to 8.0%). The higher percent loss in the 5 and 20 mg/kg groups resulted from one dam in each exposure group with whole litter resorptions.

Table 10 Summary of Uterine Content Data for Rats in the Prenatal Developmental Toxicity Gavage Study of Vinpocetine

| 0 mg/kg | 5 mg/kg | 20 mg/kg | 60 mg/kg
Pregnancy Summary
Mated females | 25 | 25 | 25 | 25
Pregnant females | 21 | 20 | 22 | 20
Pregnant females examined on GD 21^a^ | 21 | 20 | 22 | 20
Corpora lutea per female^b^ | 15.86 ± 0.58 (21) | 16.00 ± 0.70 (20) | 15.41 ± 0.42 (22) | 16.70 ± 0.44 (20)
Implantations per female^b^ | 14.38 ± 0.49 (21) | 12.55 ± 0.92 (20) | 12.82 ± 0.85 (22) | 12.95 ± 1.04 (20)
Percent postimplantation loss^b^ | 3.29 ± 1.33** (21) | 10.67 ± 5.29 (20) | 11.13 ± 4.65 (22) | 83.13 ± 6.47** (20)
Total resorptions per litter^b^ | 0.38 ± 0.15** (21) | 0.60 ± 0.21 (20) | 0.95 ± 0.27 (22) | 10.40 ± 1.21** (20)
Early resorptions per litter^b^ | 0.33 ± 0.14** (21) | 0.60 ± 0.21 (20) | 0.86 ± 0.27 (22) | 10.40 ± 1.21** (20)
Late resorptions per litter^b^ | 0.05 ± 0.05 (21) | 0.00 ± 0.00 (20) | 0.09 ± 0.06 (22) | 0.00 ± 0.00 (20)
Dead fetuses per litter^b^ | 0.05 ± 0.05 (21) | 0.00 ± 0.00 (20) | 0.00 ± 0.00 (22) | 0.00 ± 0.00 (20)
Number of Early Resorptions^c^ | 7 | 12 | 19 | 208
Number of late resorptions^c^ | 1 | 0 | 2 | 0
Number of whole litter resorptions^a^ | 0** | 1 | 1 | 12**
Number of dead fetuses^c^ | 1 | 0 | 0 | 0
Live Fetuses^b^
Number of live fetuses | 293 | 239 | 261 | 51
Live fetuses per litter | 13.95 ± 0.55** (21) | 11.95 ± 1.06 (20) | 11.86 ± 0.88 (22) | 2.55 ± 1.00** (20)
Live male fetuses per litter | 6.38 ± 0.42** (21) | 4.95 ± 0.62 (20) | 5.50 ± 0.59 (22) | 1.80 ± 0.69** (20)
Live female fetuses per litter | 7.57 ± 0.57** (21) | 7.00 ± 0.74 (20) | 6.36 ± 0.60 (22) | 0.75 ± 0.42** (20)
Percent live male fetuses per litter | 46.47 ± 2.99 (21) | 41.63 ± 3.55 (19) | 45.74 ± 3.44 (21) | 82.19 ± 8.29* (8)
Fetal Weight (g)^d^
Fetal weight per litter | 5.15 ± 0.07 (21) | 5.29 ± 0.16 (19) | 5.21 ± 0.12 (21) | 5.11 ± 0.10 (8)
Male fetal weight per litter | 5.28 ± 0.06 (21) | 5.49 ± 0.21 (19) | 5.35 ± 0.12 (21) | 5.18 ± 0.08 (8)
Female fetal weight per litter | 5.03 ± 0.07 (21) | 5.10 ± 0.10 (19) | 5.09 ± 0.12 (21) | 4.63 ± 0.06 (4)
Gravid Uterine Weight (g)^e^
Gravid uterine weight | 97.79 ± 3.11** (21) | 83.89 ± 6.59 (20) | 85.07 ± 5.28 (22) | 19.52 ± 6.53** (20)
Terminal body weight | 385.7 ± 4.2** (21) | 368.5 ± 8.2 (20) | 370.0 ± 5.5 (22) | 296.1 ± 8.2** (20)
Adjusted body weight | 287.89 ± 2.33* (21) | 284.58 ± 3.60 (20) | 284.90 ± 2.20 (22) | 276.60 ± 2.79* (20)

Values are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to the end of the study.

* Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column).

** p ≤ 0.01.

GD = gestation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ No statistical analyses were performed on number of early resorptions, number of late resorptions, or number of dead fetuses.

^d^ Statistical analysis performed using a mixed-effects linear model with litter as a random effect (trend and pairwise).

^e^ Statistical analysis performed by the Jonckheere (trend) and the Williams or Dunnett (pairwise) tests; adjusted body weight = terminal body weight minus gravid uterine weight.

There was a smaller number of litters at 60 mg/kg. Although no exposure-related effects on male fetal body weights were noted, female fetal body weights averaged slightly less (8%) than for the vehicle control group (Table 10). The fetal sex ratio was statistically higher in the 60 mg/kg group (82% male) than in the vehicle control group (46% male); however, with the small number of viable litters and fetuses available for assessment, the finding was considered spurious.

### Fetal Findings

#### External

Fetal external abnormalities were unrelated to vinpocetine exposure and limited to singular occurrences of generalized subcutaneous edema in the 5 and 20 mg/kg groups, a singular occurrence of omphalocele in the 20 mg/kg group, and singular occurrence of a bent or short tail in two separate fetuses in the 20 mg/kg group (Appendix E^50^).

#### Visceral

An exposure-related effect was observed in the heart: increased incidences of ventricular septum defects (VSDs), a malformation, occurred in 0%, 1.3%, 3.1%, and 3.9% of the fetuses (and 0%, 15.8%, 33.3%, and 25.0% of litters) in the 0, 5, 20, and 60 mg/kg groups, respectively (Table 11; Appendix E^50^). The NTP historical control range for VSDs is 0% to 0.5% for affected fetuses and litters, respectively. Several other visceral and skeletal abnormalities were noted in two and four fetuses with VSDs in the 5 and 20 mg/kg groups and in one fetus in the 60 mg/kg group; however, no other fetal malformations were observed in the remainder of the fetuses with VSDs.

Table 11 Summary of Selected Fetal Visceral Findings in Rats in the Prenatal Developmental Toxicity Gavage Study of Vinpocetine

| 0 mg/kg | 5 mg/kg | 20 mg/kg | 60 mg/kg
Number of Fetuses Examined | 293 | 239 | 261 | 51
Number of Litters Examined | 21 | 19 | 21 | 8
Heart
Aortic valve, misshapen – [M]
Fetuses | 19 (6.48) | 14 (5.86) | 17 (6.51) | 0 (0.0)*
Litters | 12 (57.14)** | 11 (57.89) | 10 (47.62) | 0 (0.00)**
Atrium, right, large – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 1 (0.38) | 0 (0.0)
Litters | 0 (0.00) | 0 (0.00) | 1 (4.76) | 0 (0.00)
Ventricle, ventricular septum defect – [M]^a^
Fetuses | 0 (0.0)** | 3 (1.26) | 8 (3.07)** | 2 (3.92)*
Litters | 0 (0.00) | 3 (15.79) | 7 (33.33)** | 2 (25.00)
Ventricle, left, thick wall – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 1 (0.38) | 0 (0.0)
Litters | 0 (0.00) | 0 (0.00) | 1 (4.76) | 0 (0.00)
Major Vessels
Carotid artery, right, supernumerary – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (1.96)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (12.50)
Ductus arteriosus, patent – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 1 (0.38) | 0 (0.0)
Litters | 0 (0.00) | 0 (0.00) | 1 (4.76) | 0 (0.00)
Innominate artery, absent – [V]
Fetuses | 4 (1.37) | 7 (2.93) | 8 (3.07) | 1 (1.96)
Litters | 4 (19.05) | 6 (31.58) | 5 (23.81) | 1 (12.50)
Innominate artery, short – [V]
Fetuses | 3 (1.02) | 4 (1.67) | 2 (0.77) | 1 (1.96)
Litters | 3 (14.29) | 4 (21.05) | 2 (9.52) | 1 (12.50)

Upper row denotes number of affected fetuses and (%) and lower row the number of affected litters and (%).

Statistical analysis for litter data and for fetal data (without the litter effects) performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

* Statistically significant (p ≤ 0.05) trend (denoted in the vehicle control column) or pairwise comparison (denoted in the dose group column); **(p ≤ 0.01). Statistical analysis of fetuses with litter-based adjustments performed by mixed-effects logistic regression models found no statistically significant trend or pairwise comparison.

[M] = malformation; [V] = variation.

^a^ Historical incidence for control groups for all routes: fetuses – 2/1,326 (0.15%), range 0.00–0.48%; litters – 2/104 (1.92%), range 0.00–5.26%.

Other malformations in the heart included misshapen aortic valves, large right atrium, and thick left ventricle wall (Table 11); however, those findings were not considered to be exposure related because of the high background incidence (misshapen aortic valves) or occurrence in a single fetus (large right atrium and thick left ventricle wall).

In the major vessels and thoracic viscera, there were singular occurrences of a supernumerary right carotid artery, patent ductus arteriosus, absent lung lobe accessory, fused right cranial lung lobe, thin diaphragm, and a diaphragm hernia and multiple occurrences of absent innominate arteries and short innominate arteries (Appendix E^50^). These findings were considered incidental, and not exposure related, because they are a common background finding (absent or short innominate arteries)^79^ or exhibited no trend with dose.

#### Head

Malformations observed in vinpocetine-treated groups included a single incidence of hydrocephaly in one fetus in the 5 mg/kg group (Appendix E^50^). Additionally, a single fetus in the 20 mg/kg group had the variation of dilated ventricles. These findings were incidental and were not considered to be exposure related.

#### Skeletal

In the fetal vertebrae, there was a significant trend for increased incidences of incomplete ossification throughout the thoracic centra that was considered exposure related due to dose-dependent increases by pairwise comparison in the 20 and 60 mg/kg groups (Table 12; Appendix E^50^). The incidence of this variation at 60 mg/kg (17%) exceeded the historical control range (0% to 0.82%). Additional exposure-related findings included supernumerary ribs that occurred in a dose-dependent manner and that were present in multiple litters per group. Significant trends of increasing incidence with increasing dose were noted for full (malformation) and short (less than one third the length of the rib above it; variation) thoracolumbar ribs (Table 12). An increased number of fetuses was found with full supernumerary thoracolumbar ribs on the left, right, and bilaterally, which culminated in total incidences of full supernumerary thoracolumbar ribs in 4.6% and 25.5% of the fetuses in the 20 and 60 mg/kg groups, respectively. This increased incidence was statistically significant by pairwise comparison at 60 mg/kg (p ≤ 0.01). Although increased incidences of short supernumerary thoracolumbar ribs are a common background lesion in this strain of rat, the findings were statistically significant for both the trend test and pairwise comparison at 20 and 60 mg/kg (p ≤ 0.05), which supports the idea that increases of full supernumerary thoracolumbar ribs were exposure related.

Table 12 Summary of Selected Fetal Skeletal Findings in Rats in the Prenatal Developmental Toxicity Gavage Study of Vinpocetine

| 0 mg/kg | 5 mg/kg | 20 mg/kg | 60 mg/kg
Number of Fetuses Examined | 293 | 239 | 260 | 47
Number of Litters Examined | 21 | 19 | 21 | 7
Vertebrae
Cervical arch, multiple sites, misshapen – [M]
Fetuses | 0 (0.0) | 1 (0.42) | 0 (0.0) | 0 (0.0)
Litters | 0 (0.00) | 1 (5.26) | 0 (0.00) | 0 (0.00)
Thoracic arch, 6th right, misshapen – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (2.13)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (14.29)
Thoracic arch, multiple sites, misshapen – [M]
Fetuses | 0 (0.0) | 1 (0.42) | 0 (0.0) | 0 (0.0)
Litters | 0 (0.00) | 1 (5.26) | 0 (0.00) | 0 (0.00)
Thoracic centrum, 1st, hemicentric – [V]
Fetuses | 0 (0.0) | 1 (0.42) | 0 (0.0) | 0 (0.0)
Litters | 0 (0.00) | 1 (5.26) | 0 (0.00) | 0 (0.00)
Thoracic centrum, 12th, hemicentric – [V]
Fetuses | 0 (0.0) | 1 (0.42) | 0 (0.0) | 0 (0.0)
Litters | 0 (0.00) | 1 (5.26) | 0 (0.00) | 0 (0.00)
Thoracic centrum, 1st, incomplete ossification – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 1 (0.38) | 0 (0.0)
Litters | 0 (0.00) | 0 (0.00) | 1 (4.76) | 0 (0.00)
Thoracic centrum, 5th, incomplete ossification – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 1 (0.38) | 0 (0.0)
Litters | 0 (0.00) | 0 (0.00) | 1 (4.76) | 0 (0.00)
Thoracic centrum, 6th, incomplete ossification – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (2.13)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (14.29)
Thoracic centrum, 9th, incomplete ossification – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (2.13)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (14.29)
Thoracic centrum, 10th, incomplete ossification – [V]
Fetuses | 1 (0.34) | 0 (0.0) | 0 (0.0) | 1 (2.13)
Litters | 1 (4.76) | 0 (0.00) | 0 (0.00) | 1 (14.29)
Thoracic centrum, 11th, incomplete ossification – [V]
Fetuses | 0 (0.0)** | 0 (0.0) | 3 (1.15) | 2 (4.26)*
Litters | 0 (0.00)** | 0 (0.00) | 3 (14.29) | 2 (28.57)
Thoracic centrum, 12th, incomplete ossification – [V]
Fetuses | 0 (0.0)** | 0 (0.0) | 1 (0.38) | 3 (6.38)**
Litters | 0 (0.00)** | 0 (0.00) | 1 (4.76) | 2 (28.57)
Thoracic centrum, 13th, incomplete ossification – [V]
Fetuses | 0 (0.0)** | 0 (0.0) | 0 (0.0) | 2 (4.26)*
Litters | 0 (0.00)** | 0 (0.00) | 0 (0.00) | 2 (28.57)
Thoracic centrum, multiple sites, incomplete ossification – [V]
Fetuses | 0 (0.0) | 1 (0.42) | 0 (0.0) | 0 (0.0)
Litters | 0 (0.00) | 1 (5.26) | 0 (0.00) | 0 (0.00)
Thoracic centrum, incomplete ossification, total – [V]^a^
Fetuses | 1 (0.34)**^##^ | 1 (0.42) | 6 (2.31)*^#^ | 8 (17.02)**^##^
Litters | 1 (4.76)** | 1 (5.26) | 5 (23.81) | 3 (42.86)*
Lumbar arch, 5th left, fused – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (2.13)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (14.29)
Lumbar centrum, 5th, fused – [M]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 1 (2.13)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 1 (14.29)
Lumbar centrum, 1st, incomplete ossification – [V]
Fetuses | 0 (0.0) | 1 (0.42) | 0 (0.0) | 0 (0.0)
Litters | 0 (0.00) | 1 (5.26) | 0 (0.00) | 0 (0.00)
Lumbar centrum, 3rd, incomplete ossification – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 1 (0.38) | 0 (0.0)
Litters | 0 (0.00) | 0 (0.00) | 1 (4.76) | 0 (0.00)
Presacral vertebrae, greater than 26 – [V]
Fetuses | 0 (0.0)** | 0 (0.0) | 0 (0.0) | 4 (8.51)**
Litters | 0 (0.00)** | 0 (0.00) | 0 (0.00) | 2 (28.57)
Sacral centrum, multiple sites, misshapen – [M]
Fetuses | 0 (0.0) | 1 (0.42) | 0 (0.0) | 0 (0.0)
Litters | 0 (0.00) | 1 (5.26) | 0 (0.00) | 0 (0.00)
Supernumerary Rib
Thoracolumbar, left, full – [M]
Fetuses | 0 (0.0)** | 1 (0.42) | 2 (0.77) | 3 (6.38)**
Litters | 0 (0.00) | 1 (5.26) | 2 (9.52) | 1 (14.29)
Thoracolumbar, right, full – [M]
Fetuses | 1 (0.34) | 2 (0.84) | 1 (0.38) | 1 (2.13)
Litters | 1 (4.76) | 2 (10.53) | 1 (4.76) | 1 (14.29)
Thoracolumbar, bilateral, full – [M]
Fetuses | 0 (0.0)** | 2 (0.84) | 9 (3.46)** | 8 (17.02)**
Litters | 0 (0.00) | 2 (10.53) | 1 (4.76) | 2 (28.57)
Thoracolumbar, full, total – [M]^b^
Fetuses | 1 (0.34)**^##^ | 5 (2.09) | 12 (4.62)** | 12 (25.53)**^##^
Litters | 1 (4.76)* | 3 (15.79) | 4 (19.05) | 3 (42.86)*
Thoracolumbar, left, short – [V]
Fetuses | 21 (7.17)*^#^ | 10 (4.18) | 22 (8.46) | 7 (14.89)
Litters | 13 (61.90) | 6 (31.58) | 13 (61.90) | 5 (71.43)
Thoracolumbar, right, short – [V]
Fetuses | 2 (0.68)* | 11 (4.6)**^#^ | 16 (6.15)**^##^ | 2 (4.26)^#^
Litters | 2 (9.52) | 6 (31.58) | 12 (57.14)** | 2 (28.57)
Thoracolumbar, bilateral, short – [V]
Fetuses | 6 (2.05) | 9 (3.77) | 17 (6.54)**^#^ | 1 (2.13)
Litters | 4 (19.05) | 5 (26.32) | 11 (52.38)* | 1 (14.29)
Thoracolumbar, short, total – [V]
Fetuses | 29 (9.9)**^#^ | 30 (12.55) | 55 (21.15)**^#^ | 10 (21.28)*^#^
Litters | 14 (66.67) | 10 (52.63) | 17 (80.95) | 5 (71.43)

Upper row denotes number of affected fetuses and (%); lower row the number of affected litters and (%).

* Statistically significant (p ≤ 0.05) analysis for litter data and for fetal data (without the litter effects) performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests. Statistically significant trend is denoted in the vehicle control column; a significant pairwise comparison is denoted in the dose group column.

** p ≤ 0.01.

^#^ Statistically significant (p ≤ 0.05) trend (denoted in the vehicle control column) or pairwise comparison (denoted in the dose group column); statistical analysis of fetuses with litter-based adjustments performed by mixed-effects logistic regression.

^##^ p ≤ 0.01.

[M] = malformation; [V] = variation.

^a^ Historical incidence in control groups for gavage studies: fetuses – 3/1,325 (0.23%), range 0.00–0.82%; litters – 3/104 (2.88%), range 0.00%-11.11%.

^b^ Historical incidence in control groups for gavage studies: fetuses – 14/1,324 (1.06%), range 0.34–3.35%; litters – 13/104 (12.50%), range 4.76–31.58%.

In the 60 mg/kg group, there was an increased incidence of greater than 26 presacral vertebrae (Table 12). Whether this increased incidence is related to exposure is unclear; however, the incidences were outside of the historical control range (0%), and all the fetuses with this variation also had either bilateral full supernumerary ribs or left full supernumerary ribs.

Additionally, singular occurrences of incomplete ossification were noted in the lumbar centrum in the 5 and 20 mg/kg groups; the occurrences were considered incidental and not exposure related. All malformations present in the vertebrae (misshapen cervical arch, misshapen sacral centrum, misshapen thoracic arch, fused lumbar arch, and fused lumbar centrum) were limited to three fetuses and therefore were not considered related to vinpocetine exposure.

## Dose Selection Rationale for the Dose Range-finding Study in Rabbits

Dose selection for the range-finding study in rabbits was informed by both the results from the dose range-finding study in the rat and by toxicokinetic data on vinpocetine in rabbits from the literature. Toxicokinetic data on vinpocetine in rats and rabbits demonstrate similar plasma AUC and C_max_ levels.^27,28,30,33-35^ Therefore, the doses chosen for the rabbits were similar to those chosen for the dose range-finding study in rats (0, 25, 75, 150, and 300 mg/kg/day).

## Dose Range-finding Study in Rabbits

### Maternal Findings

#### Viability and Clinical Observations

All vehicle control and dosed rabbits survived until the end of the study (Table 13), with the exception of one female in the 150 mg/kg group that was removed on GD 25 due to abortion. This doe also had clinical observations beginning on GD 21 of red abnormal vaginal discharge and red substance present in the cage pan that were consistent with the abortion (Appendix E^50^). Clinical observations of red vaginal discharge and red discoloring of the vagina also occurred in one animal each from the vehicle control and 300 mg/kg groups beginning on GD 22 and GD 20, respectively. These clinical observations were not accompanied by abortions; however, postimplantation loss was noted in the doe from the 300 mg/kg group. An additional incidence of red substance in the cage pan was observed on GD 20 in a doe from the 300 mg/kg group that also had 66.7% postimplantation loss.

Table 13 Maternal Disposition of Rabbits in the Dose Range-finding Gavage Study of Vinpocetine

| 0 mg/kg | 25 mg/kg | 75 mg/kg | 150 mg/kg | 300 mg/kg
Time-mated females | 8 | 8 | 8 | 8 | 8
Pregnant (on GD 29) | 8 | 7 | 8 | 7 | 8
Euthanasia aborted-pregnant | 0 | 0 | 0 | 1^a^ | 0
Nonpregnant (on GD 29) | 0 | 1 | 0 | 0 | 0

GD = gestation day.

^a^ Doe removed on GD 25.

#### Body Weights and Feed Consumption

Treatment-related decreases in maternal body weights were noted from GD 12 to GD 29 in the 300 mg/kg group, relative to the vehicle control group (Figure 6; Table 14). Decreases in mean maternal body weight gains, compared to vehicle controls, were 44% and 34% for the 150 and 300 mg/kg groups, respectively (Table 14). Feed consumption decreased at 150 and 300 mg/kg (Table 15) and embryo-fetal loss increased at 300 mg/kg (20.4% compared to 1.4% in the vehicle control group; Table 16). Daily mean body weight changes for does in each dose group are available in Appendix E.^50^

Figure 6

Maternal Growth Curves for Pregnant Rabbits Administered Vinpocetine by Gavage in the Dose Range-finding Study

Information for statistical significance in maternal weights is provided in Table 14 and Appendix E.^50^

Table 14 Summary of Maternal Body Weight Gains of Rabbits in the Dose Range-finding Gavage Study of Vinpocetine^a^

Gestation Day Interval | 0 mg/kg | 25 mg/kg | 75 mg/kg | 150 mg/kg | 300 mg/kg
7–29 | 460.2 ± 33.8** (8) | 458.2 ± 46.2 (7) | 399.3 ± 58.4 (8) | 256.7 ± 40.9** (7) | 304.1 ± 33.2** (8)
3–7 | 81.5 ± 17.7 (8) | 61.6 ± 20.1 (7) | 108.0 ± 10.7 (8) | 69.2 ± 19.3 (8) | 45.3 ± 13.1 (8)
7–9 | 53.2 ± 8.2 (8) | 61.6 ± 11.1 (7) | 49.1 ± 10.8 (8) | 14.9 ± 19.9 (8) | 47.3 ± 29.3 (8)
9–12 | 56.8 ± 15.1 (8) | 60.8 ± 13.4 (7) | 74.9 ± 22.4 (8) | 40.9 ± 16.0 (8) | 26.8 ± 19.6 (8)
12–15 | 105.3 ± 11.1** (8) | 97.7 ± 10.2 (7) | 71.5 ± 17.8 (8) | 36.1 ± 36.7 (8) | 46.0 ± 20.7 (8)
15–18 | 20.0 ± 9.5 (8) | 19.4 ± 9.3 (7) | 11.0 ± 10.2 (8) | 12.5 ± 9.9 (8) | 11.0 ± 11.8 (8)
18–21 | 56.3 ± 12.6 (8) | 43.8 ± 10.0 (7) | 39.3 ± 11.3 (8) | 55.5 ± 23.8 (8) | 47.4 ± 23.6 (8)
21–24 | 82.2 ± 6.7 (8) | 71.5 ± 18.1 (7) | 88.0 ± 12.7 (8) | 44.0 ± 10.8 (8) | 71.4 ± 15.3 (8)
24–27 | 76.0 ± 11.5** (8) | 48.4 ± 14.6 (7) | 18.4 ± 18.6** (8) | 24.9 ± 11.7* (7) | 7.3 ± 12.4** (8)
27–29 | 10.3 ± 16.2 (8) | 55.5 ± 8.0 (7) | 47.1 ± 9.6 (8) | 38.7 ± 15.4 (7) | 46.9 ± 17.6 (8)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Williams or Dunnett test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Body weight gains for pregnant females are given in grams. Data are displayed as mean ± standard error (n).

Table 15 Summary of Maternal Feed Consumption of Rabbits in the Dose Range-finding Gavage Study of Vinpocetine^a^

Gestation Day Interval | 0 mg/kg | 25 mg/kg | 75 mg/kg | 150 mg/kg | 300 mg/kg
7–29 | 137.6 ± 4.3** (8) | 131.8 ± 5.7 (7) | 125.2 ± 4.0 (8) | 101.3 ± 11.4** (7) | 113.8 ± 8.9* (8)
3–7 | 149.1 ± 0.8 (8) | 143.2 ± 7.1 (7) | 149.8 ± 0.5 (8) | 139.6 ± 7.6 (8) | 147.4 ± 2.6 (8)
7–9 | 148.9 ± 2.0* (8) | 143.0 ± 5.3 (7) | 148.7 ± 2.1 (8) | 131.1 ± 9.0 (8) | 118.7 ± 15.4 (8)
9–12 | 145.1 ± 4.3* (8) | 141.1 ± 5.5 (7) | 137.4 ± 6.7 (8) | 107.3 ± 13.4 (8) | 106.1 ± 18.6 (8)
12–15 | 128.6 ± 9.4 (8) | 131.8 ± 8.1 (7) | 117.6 ± 9.9 (8) | 92.5 ± 20.9 (8) | 102.9 ± 18.3 (8)
15–18 | 142.9 ± 4.1* (8) | 138.7 ± 6.7 (7) | 118.5 ± 10.9 (8) | 98.7 ± 20.0 (8) | 109.6 ± 15.9 (8)
18–21 | 148.0 ± 2.4** (8) | 137.9 ± 6.3 (7) | 132.5 ± 6.7 (8) | 109.3 ± 8.7** (8) | 131.2 ± 6.0* (8)
21–24 | 142.6 ± 5.2 (8) | 127.8 ± 10.8 (7) | 137.1 ± 6.1 (8) | 117.2 ± 8.6 (8) | 127.3 ± 5.9 (8)
24–27 | 134.7 ± 5.6* (8) | 126.9 ± 9.1 (7) | 106.6 ± 8.8 (8) | 89.8 ± 10.6** (7) | 110.3 ± 3.2 (8)
27–29 | 96.1 ± 14.4 (8) | 100.7 ± 18.4 (7) | 95.0 ± 24.2 (8) | 97.1 ± 14.3 (7) | 102.0 ± 16.2 (8)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Shirley or Dunn test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Feed consumption for pregnant females is given in grams/day. Data are displayed as mean ± standard error (n).

Table 16 Summary of Uterine Content Data for Rabbits in the Dose Range-finding Gavage Study of Vinpocetine

| 0 mg/kg | 25 mg/kg | 75 mg/kg | 150 mg/kg | 300 mg/kg
Pregnancy Summary
Mated females | 8 | 8 | 8 | 8 | 8
Pregnant females | 8 | 7 | 8 | 8 | 8
Pregnant females examined on GD 29^a^ | 8 | 7 | 8 | 7 | 8
Corpora lutea per female^b^ | 9.50 ± 0.38 (8) | 8.71 ± 0.47 (7) | 9.63 ± 0.53 (8) | 8.86 ± 0.40 (7) | 9.13 ± 0.61 (8)
Implantations per female^b^ | 9.25 ± 0.41 (8) | 8.00 ± 0.44 (7) | 9.25 ± 0.56 (8) | 7.71 ± 0.68 (7) | 8.38 ± 0.56 (8)
Percent postimplantation loss^b^ | 1.39 ± 1.39 (8) | 3.37 ± 2.18 (7) | 2.53 ± 1.66 (8) | 3.57 ± 3.57 (7) | 20.42 ± 9.05 (8)
Total resorptions per litter^b^ | 0.13 ± 0.13 (8) | 0.14 ± 0.14 (7) | 0.25 ± 0.16 (8) | 0.14 ± 0.14 (7) | 1.88 ± 0.85 (8)
Early resorptions per litter^b^ | 0.13 ± 0.13* (8) | 0.00 ± 0.00 (7) | 0.00 ± 0.00 (8) | 0.14 ± 0.14 (7) | 1.63 ± 0.71 (8)
Late resorptions per litter^b^ | 0.00 ± 0.00 (8) | 0.14 ± 0.14 (7) | 0.25 ± 0.16 (8) | 0.00 ± 0.00 (7) | 0.25 ± 0.25 (8)
Dead fetuses per litter^b^ | 0.00 ± 0.00 (8) | 0.14 ± 0.14 (7) | 0.00 ± 0.00 (8) | 0.00 ± 0.00 (7) | 0.00 ± 0.00 (8)
Number of early resorptions^c^ | 1 | 0 | 0 | 1 | 13
Number of late resorptions^c^ | 0 | 1 | 2 | 0 | 2
Number of whole litter resorptions | 0 | 0 | 0 | 0 | 0
Number of dead fetuses^c^ | 0 | 1 | 0 | 0 | 0
Live Fetuses^b^
Number of live fetuses | 73 | 54 | 72 | 53 | 52
Live fetuses per litter | 9.13 ± 0.44* (8) | 7.71 ± 0.42 (7) | 9.00 ± 0.53 (8) | 7.57 ± 0.81 (7) | 6.50 ± 0.73* (8)
Live male fetuses per litter | 3.50 ± 0.94 (8) | 3.86 ± 0.63 (7) | 4.63 ± 0.38 (8) | 3.86 ± 0.91 (7) | 3.38 ± 0.73* (8)
Live female fetuses per litter | 5.63 ± 0.68* (8) | 3.86 ± 0.70 (7) | 4.38 ± 0.63 (8) | 3.71 ± 0.42 (7) | 3.13 ± 0.67 (8)
Percent live male fetuses per litter | 36.30 ± 8.71 (8) | 50.68 ± 8.87 (7) | 52.67 ± 5.63 (8) | 45.15 ± 9.80 (7) | 50.80 ± 9.02 (8)
Fetal Weight (g)^d^
Fetal weight per litter | 39.72 ± 1.33** (8) | 41.47 ± 0.95 (7) | 37.53 ± 0.90 (8) | 39.36 ± 1.74 (7) | 35.78 ± 1.15 (8)
Male fetal weight per litter | 40.87 ± 1.59** (8) | 42.70 ± 0.97 (7) | 38.50 ± 1.15 (8) | 38.06 ± 1.62 (6) | 36.49 ± 2.00 (8)
Female fetal weight per litter | 38.76 ± 1.57* (8) | 40.37 ± 1.12 (7) | 36.35 ± 1.01 (8) | 39.29 ± 1.75 (7) | 34.65 ± 0.95 (8)
Gravid Uterine Weight (g)^e^
Gravid uterine weight | 515.25 ± 14.70** (8) | 470.05 ± 20.66 (7) | 483.91 ± 32.24 (8) | 421.86 ± 39.25* (7) | 340.94 ± 27.73** (8)
Terminal body weight | 3,449.4 ± 64.6* (8) | 3,406.5 ± 58.0 (7) | 3,467.7 ± 95.0 (8) | 3,358.4 ± 105.6 (7) | 3,271.4 ± 34.2 (8)
Adjusted body weight | 2,984.19 ± 64.86 (8) | 2,936.41 ± 42.60 (7) | 2,983.75 ± 75.64 (8) | 2,936.53 ± 110.63 (7) | 2,930.44 ± 46.81 (8)

Values are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to the end of the study.

GD = gestation day.

* Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column).

** p ≤ 0.01.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ No statistical analyses were performed on number of early resorptions, number of late resorptions, or number of dead fetuses.

^d^ Statistical analysis performed using a mixed-effects linear model with litter as a random effect (trend and pairwise).

^e^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests. Adjusted body weight = terminal body weight minus gravid uterine weight.

Treatment-related maternal feed consumption decreased in the 150 and 300 mg/kg groups during gestation (Table 15). Decreases in feed consumption across several dosing intervals (11% to 30% in both high-dose groups compared to the vehicle control group) culminated in overall decreases of 17% and 26% for 150 and 300 mg/kg groups, respectively, during the GD 7 to GD 29 interval.

#### Maternal and Litter Observations

At necropsy, there were no notable maternal gross pathology findings (Appendix E^50^). There was an exposure-related effect on embryo-fetal survival in the 300 mg/kg group (Table 16). Uterine examination revealed fewer live fetuses per litter in the 300 mg/kg group (mean of 6.5 compared to 9.1 in the vehicle control group), which was associated with an increase in early resorptions per litter (mean of 1.6 compared to 0.1 per litter in the vehicle control group). Overall, these findings in the 300 mg/kg group led to an increase in percent postimplantation loss (20.4% compared to 1.4% in the vehicle control group) which was associated with a 34% reduction in mean gravid uterine weight. No exposure-related effects were found on embryo-fetal survival in any group administered 150 mg/kg or less.

Mean fetal weights were reduced for both males and females in the 300 mg/kg group (10.7% and 10.6% less than the vehicle control group, respectively). No effects were noted at the lower doses.

### Fetal Findings

#### External

There were no external malformations or variations attributed to vinpocetine exposure at 25, 75, 150, or 300 mg/kg per day (Appendix E^50^). External findings were limited to a singular occurrence of localized subcutaneous edema in the 75 mg/kg group and one incidence of subcutaneous hemorrhage in each of the vehicle control, 25, and 150 mg/kg groups; those were considered incidental and unrelated to vinpocetine exposure.