# Materials and Methods

## Overview of Prenatal Developmental Toxicity Study Designs

Prenatal developmental toxicity studies are conducted to ascertain if in utero exposure to a test agent results in embryo-fetal death, structural malformations/variations, growth retardation, or functional deficits not secondary to overt maternal toxicity. Overt maternal toxicity has been shown to affect normal embryo-fetal growth and development (e.g., excessively lower maternal body weight gains and lower fetal weights, increased maternal stress in mice, and cleft palate).^51-53^ The presence of maternal toxicity, however, should not negate a priori an apparent fetal response. Rather, given the maternal/embryo-fetal interrelationship, maternal responses should be considered when interpreting fetal findings. Pregnant animals should be administered the highest feasible dose levels of test agent (or the limit dose) to achieve maximal dam and fetal exposure and sufficiently challenge the test system to identify potential developmental hazards.^54^

The conduct of a dose range-finding study helps determine dose selection when the potential for test agent-induced maternal toxicity is unknown and can provide preliminary information on embryo-fetal outcomes (e.g., postimplantation loss, changes in fetal weight, external defects) and informs the design for a prenatal developmental toxicity study. In the prenatal developmental toxicity study, fetal examination is expanded to include examination of the fetal viscera, head (soft tissue and skeletal components), and the skeleton for osseous and cartilaginous defects. Abnormalities are categorized in one of two groups: (1) malformations that are permanent structural changes that could adversely affect survival, development, or function; and (2) variations that are a divergence beyond the usual range of structural constitution but might not adversely affect survival or health,^52^ consistent with the descriptions by Makris et al.^55^ The general study design for the dose range-finding and prenatal developmental toxicity studies in the rat is presented in Figure 2, and the general study design for a dose range-finding rabbit study is presented in Figure 3.

Figure 2

Design of Dose Range-finding and Prenatal Developmental Toxicity Studies in Rats

^a^Animals are exposed once daily from gestation day (GD) 6 to GD 20 and necropsied on GD 21.

^b^All fetuses are examined externally (including inspection of the oral cavity). Fetuses in the prenatal developmental toxicity study also are also examined for visceral and skeletal effects with approximately 50% of the heads examined for soft tissue alterations.

Figure 3

Design of Dose Range-finding Prenatal Developmental Toxicity Study in Rabbits

^a^Animals are exposed once daily from gestation day (GD) 7 to GD 28 and necropsied on GD 29.

^b^All fetuses are examined externally (including inspection of the oral cavity).

## Procurement and Characterization

### Vinpocetine

Vinpocetine was obtained from Maypro Industries, LLC (Purchase, NY) in one lot (VA201211001). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH) (Appendix A). The chemical, a white crystalline powder, was identified as vinpocetine using Fourier transform infrared (FTIR) and proton and carbon-13 nuclear magnetic resonance spectroscopy and gas chromatography (GC) with mass spectrometry detection. The optical activity analysis indicated an average rotation of +131.6°, which is consistent with the optical rotation of vinpocetine. Purity of the test article was determined by elemental analyses, proton-induced X-ray emission (PIXE) spectroscopy, differential scanning calorimetry, melting point analysis, high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection, and GC with flame ionization detection (FID).

Karl Fischer titration indicated less than 0.07% water. Elemental analyses for carbon, hydrogen, nitrogen, and oxygen agreed with the theoretical values for vinpocetine; PIXE analyses indicated no inorganic impurities greater than 0.1%. Melting point analysis averaged 149.88°C and differential scanning calorimetry indicated a purity of 99.9%. HPLC/UV indicated one major peak (99.5% of the total peak area) and two impurities greater than 0.1% of the total peak area (0.17% and 0.28%). The larger impurity peak was tentatively identified as apovincamine. GC/FID indicated one major peak (99.3% of the total peak area) and one reportable impurity (0.67% of the total peak area), which was tentatively identified as apovincamine. Screening for volatiles using a second GC/FID system indicated the presence of 0.018% methylene chloride. The overall purity of lot VA201211001 was determined to be greater than 99.3%.

Stability studies of the bulk chemical were performed using GC/FID. These studies indicated that vinpocetine was stable as a bulk chemical for at least 14 days when stored in sealed amber glass vials at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature and protected from light in sealed double plastic bags in a plastic bucket. Reanalysis of the bulk chemical was performed twice during the studies with GC/FID, and no degradation was detected.

### Methylcellulose

Methylcellulose was obtained from Spectrum Chemical Manufacturing Corporation (Gardena, CA) in two lots (2CB0045 and 2DH0326); lot 2CB0045 was used in the dose range-finding study in rats, and lot 2DH0326 was used in the prenatal developmental toxicity study in rats and the dose range-finding study in rabbits. Lot 2DH0326 was identified as methylcellulose using FTIR spectroscopy. Duplicate determinations of the methoxy content (30.9% and 31.1%) were within the acceptance limits of 26.0–33.0%.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared once for each study by mixing vinpocetine with 0.5% aqueous methylcellulose solution. The analytical chemistry laboratory used GC/FID to evaluate the homogeneity of 0.1 and 200 mg/mL formulations, syringeability for 18- and 22-gauge gavage needles using the 200 mg/mL formulation, resuspendability of the 200 mg/mL formulation, and stability of the 0.1 mg/mL formulation. Homogeneity, syringeability, and resuspendability were confirmed. Stability was confirmed for 42 days for dose formulations stored in clear glass bottles with Teflon^®^-lined lids packaged in sealed amber plastic bags at room temperature and for 3 hours under simulated animal room conditions.

Periodic analyses of the dose formulations of vinpocetine were conducted by the analytical chemistry laboratory using GC/FID. During the dose range-finding study in rats, dose formulations were analyzed once: all five dose formulations analyzed and used were within 10% of the target concentrations (Table A-3). Animal room samples of these dose formulations were also analyzed; four of five were within 10% of the target concentrations. During the prenatal developmental toxicity study in rats, the dose formulations were analyzed once; animal room samples of these dose formulations were also analyzed (Table A-4). All three dose formulations and all three animal room samples were within 10% of the target concentrations. During the dose range-finding study in rabbits, the dose formulations were analyzed once (Table A-5). Of the dose formulations analyzed during the study, all eight were within 10% of the target concentrations; two of four animal room samples were within 10% of the target concentrations.

## Animal Source

Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats for use in the dose range-finding and prenatal developmental toxicity studies were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) (Table 1). This stock is routinely used in NTP studies for toxicity evaluation. Sexually mature (12–13 weeks old) females were time-mated overnight at the vendor and were received on gestation day (GD) 1 or 2 for both the dose range-finding and prenatal developmental toxicity studies. GD 0 was defined as the day that positive evidence of mating was observed.

Table 1 Experimental Design and Materials and Methods in the Dose Range-finding and Prenatal Developmental Toxicity Gavage Studies of Vinpocetine in Rats

Dose Range-finding Study | Prenatal Developmental Toxicity Study
Study Laboratory
Southern Research (Birmingham, AL) | Southern Research (Birmingham, AL)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN)
Day of Arrival
February 19, 2014 (GD 1 or 2) | January 14 or 16, 2015 (GD 1 or 2)
Average Age on Arrival
12 weeks | 12 to 13 weeks
Weight Range at Randomization
201.7 g to 256.4 g on GD 3 | 190.4 g to 260.2 g on GD 3
Calendar Day of First Dose and Last Dose
GD 6 (February 23 or 24, 2014) and GD 20 (March 9 or 10, 2014); staggered start | GD 6 (January 18 to 21, 2015) and GD 20 (February 1 to 4, 2015); staggered start
Duration of Dosing
GD 6 to 20, once daily | GD 6 to 20, once daily
Size of Study Groups
10 time-mated females | 25 time-mated females
Method of Randomization and Identification
Time-mated animals were uniquely identified on day of receipt by tail marking. Animals were assigned to one of six exposure groups by stratified randomization of GD 3 body weights using Instem Provantis^®^ (version 8) electronic data collection system. Each animal was assigned a unique animal number in Provantis^®^. This number was linked to the respective tattoo and all data collected during the study was associated with the Provantis^®^ animal number. | Same as dose range-finding study; animals assigned to one of four exposure groups using Instem Provantis^®^ (version 9) electronic data collection system.
Animals per Cage
1 | 1
Diet
Irradiated NIH-07 0.5-inch Certified Rodent Diet pellets or wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum | Same as dose range-finding study
Water
Tap water (Birmingham Water Works Co., Birmingham, AL, municipal supply) via automatic watering system, available ad libitum | Same as dose range-finding study
Cages
Solid bottom polycarbonate cages (Lab Products, Seaford, DE), changed weekly | Same as dose range-finding study
Bedding
Certified irradiated Sani-Chips® hardwood cage bedding (P.J. Murphy Forest Products Corporation, Montville, NJ), changed weekly | Same as dose range-finding study
Cage Filters
Spunbonded Remay (Andico, Birmingham, AL), changed every 2 weeks | Same as dose range-finding study
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks | Same as dose range-finding study
Animal Room Environment
Temperature: 72°F ±3°F Relative humidity: 50% ±15% Room fluorescent light: 12 hours/day Room air changes: at least 10 /hour | Same as dose range-finding study
Doses
0, 20, 40, 80, 160, or 320 mg/kg in 0.5% methylcellulose (dosing volume 5 mL/kg) | 0, 5, 20, or 60 mg/kg in 0.5% aqueous methylcellulose (dosing volume 5 mL/kg)
Type and Frequency of Observation of Dams
Observed for viability (cageside) twice daily from GD 3 through GD 20. Clinical observations (out of cage) were performed at least once during the prestudy period and at least once daily while on study (1 to 3 hours post-dose). Animals were weighed daily beginning on GD 3. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21. | Observed for viability (cageside) at least twice daily from GD 3 through GD 20. Clinical observations (out of cage) were performed at least once during the prestudy period and at least once daily while on study (1 to 3 hours post-dose). Animals were weighed on the day of arrival, on GD 3, and on GD 6 through 21. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21.
Primary Method of Euthanasia
100% CO_2_ (adults) or intraperitoneal injection of a solution containing sodium pentobarbital followed by bilateral pneumothorax or decapitation (fetuses) | Same as dose range-finding study
Necropsy and Postmortem Evaluation of Females
On GD 21, terminal body and gravid uterine weights were recorded and the uterine contents examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live or dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained to visualize potential evidence of implantation sites. For animals removed early, gross necropsy including an examination of the thoracic and abdominal viscera was performed. The uterus of each female was examined to determine pregnancy status or, if no evidence of pregnancy, stained to visualize possible early implantation sites. | On GD 21, terminal body, ovarian, and gravid uterine weights were recorded. Uterine contents were examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live or dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained to visualize potential evidence of implantation sites. For animals removed early, gross necropsy including an examination of the thoracic and abdominal viscera was performed. The uterus of each female was examined to determine pregnancy status or, if no evidence of pregnancy, stained to visualize possible early implantation sites.
Fetal Evaluation
Live fetuses were counted, sexed, weighed, and examined for external morphologic abnormalities that included inspection of the oral cavity for cleft palate. | Live fetuses were counted, sexed, weighed, and examined for external morphologic abnormalities including inspection of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were euthanized and then examined for visceral morphologic abnormalities by fresh dissection. The sex of each fetus was confirmed by internal examination. The heads from approximately one half of the fetuses in each litter were fixed, sectioned, and examined. All fetuses were eviscerated, fixed, stained, and examined for skeletal developmental variations, malformations, or other morphologic findings.

GD = gestation day.

Female New Zealand White (Hra:NZW SPF) rabbits for use in the dose range-finding study were obtained from Covance Research Products (Greenfield, IN) (Table 2). Sexually mature females (5 months old) were time-mated at the vendor and were received on GD 1 or 2.

Table 2 Experimental Design and Materials and Methods in the Dose Range-finding Gavage Study of Vinpocetine in Rabbits

Dose Range-finding Study in Rabbits
Study Laboratory
Southern Research (Birmingham, AL)
Strain and Species
New Zealand White (Hra:NZW SPF) rabbits
Animal Source
Covance Research Products (Greenfield, IN)
Day of Arrival
April 24, 2015 (GD 1 or 2)
Average Age on Arrival
5 to 6 months
Weight Range at Randomization
2,676.0 g to 3,561.6 g on GD 3
Calendar Day of First Dose (GD 7) and Last Dose (GD 28)
GD 7 (April 29 or 30, 2015) and GD 28 (May 20 or 21, 2015); staggered start
Duration of Dosing
GD 7 to 28, once daily
Size of Study Groups
8 time-mated females
Method of Randomization and Identification
Time-mated animals were individually identified by ear marking and randomized by GD 3 body weight stratification into five groups using Instem Provantis® (version 9) electronic data collection system.
Animals per Cage
1
Diet
Irradiated Purina 5322 5 LMO (Purina, Richmond, IN) and Teklad 2031 C (Harlan, Madison, WI) Certified Rabbit Diets, available ad libitum; timothy hay (BioServe, Flemington, NJ) once daily as consumable enrichment
Water
Tap water (Birmingham Water Works Co., Birmingham, AL, municipal supply) via automatic watering system, available ad libitum
Cages
Perforated-bottom stainless steel cages (Allentown Caging Equipment Co, Allentown, PA), changed every 2 weeks
Bedding
Paper cage liners (Manufacturer, City, ST), changed 3 times per week
Racks
Stainless steel (Allentown Caging Equipment Co, Allentown, PA), changed every 2 weeks
Animal Room Environment
Temperature: 61°F to 72°F Relative humidity: 30% to 70% Room fluorescent light: 12 hours/day Room air changes: at least 14/hour
Doses
0, 25, 75, 150, or 300 mg/kg in 0.5% methylcellulose (dosing volume 5 mL/kg)
Type and Frequency of Observation of Does
Observed for viability (cageside) at least twice daily from GD 3 through GD 29. Detailed observations (out of cage) were performed at least once during the prestudy period and at least once daily while on study (1 to 3 hours post-dose). Animals were weighed daily beginning on GD 3. Feed consumption was recorded at 3-day intervals from GD 3 through GD 29.
Primary Method of Euthanasia
Intravenous injection (adults) or intraperitoneal injection (fetuses) of a solution containing sodium pentobarbital
Necropsy and Postmortem Evaluation of Does
On GD 29, terminal body and gravid uterine weights were recorded, and the uterine contents were examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live and dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained to visualize potential evidence of implantation sites. For animals removed early, gross necropsy including an examination of the thoracic and abdominal viscera was performed. The uterus of each female was examined to determine pregnancy status or, if no evidence of pregnancy, stained to visualize possible early implantation sites.
Fetal Evaluation
Live fetuses were counted, sexed, weighed, and examined for external morphologic abnormalities including examination of the oral cavity for cleft palate.

GD = gestation day.

## Animal Health Surveillance

In accordance with the NTP Sentinel Animal Program (Appendix C), 10 female rabbits randomly selected from among the study groups were evaluated at the end of the dose range-finding study. Antibodies to rotavirus were detected in several samples. Rotavirus is a common virus in rabbits that was not considered to have impacted the current study.^56^ All other test results were negative. Disease screening was not conducted in the rats; however, rats were obtained from a commercial colony free of the following rat pathogens: Sendai virus, pneumonia virus of mice, sialodacryoadenitis virus, Kilham rat virus, Toolan’s H1 virus, rat minute virus, reovirus, rat theilovirus, lymphocytic choriomeningitis virus, hantavirus, mouse adenovirus, rat parvovirus, Mycoplasma pulmonis, and Pneumocystis carinii.

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals and the U.S. Animal Welfare Act and Regulations. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Southern Research Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Experimental Design

In the dose range-finding and prenatal developmental toxicity studies, time-mated rats were housed individually, provided NIH-07 feed and water ad libitum, and observed at least twice daily for viability (morning and afternoon). Clinical observations were performed on GD 3 (prenatal developmental toxicity study only) and on GD 6 through 21 until removal, typically twice daily (at the time of dose administration and cage-side post dose). Females in the dose range-finding study were weighed daily from GD 3 through GD 21, and those in the prenatal developmental study were weighed on the day of arrival, on GD 3, and daily from GD 6 through GD 21. Feed consumption was recorded for GDs 3 to 6, GD 6 to 9, GD 9 to 12, GD 12 to 15, GD 15 to 18, and GD 18 to 21. Details of the study design—including animal source and identification, diet, water, husbandry, environmental conditions, euthanasia, necropsy, and fetal evaluations—are summarized in Table 1. Information on feed composition and contaminants is provided in Appendix B and Appendix C.

In the vinpocetine rabbit dose range-finding study, time-mated animals were housed individually, provided Purina 5322 5LMO or Teklad 2031C feeds and water ad libitum, and observed at least twice daily for viability (morning and afternoon). Clinical observations were recorded on GD 3 and on GD 7 through GD 29 until removal, typically twice daily (at the time of dose administration and cage-side post dose). Females were weighed daily on GD 3 through GD 29. Feed consumption was recorded for GD 3 to 7, GD 7 to 9, GD 9 to 12, GD 12 to 15, GD 15 to 18, GD 18 to 21, GD 21 to 24, GD 24 to 27, and GD 27 to 29. Details of the rabbit study design—including animal source and identification, diet, water, husbandry, environmental conditions, euthanasia, necropsy, and fetal evaluations—are summarized in Table 2.

On GD 21, rats were weighed, euthanized by CO_2_ inhalation, and examined for gross lesions of the thoracic and abdominal cavities. On GD 29, rabbits were weighed, euthanized with intravenous injection of sodium pentobarbital-containing solution, and examined for gross lesions of the thoracic and abdominal cavities. The ovaries and gravid uterus of both species were excised and weighed (ovaries for prenatal developmental toxicology study only) and placental findings were recorded. The numbers of uterine implantation sites and corpora lutea visible on the surface of each ovary were recorded. Uterine contents were examined for pregnancy status and the number and location of all live and dead fetuses (a live fetus is defined as one that responds to stimuli; a dead fetus is defined as a term fetus that does not respond to stimuli and is not markedly autolyzed) and resorptions were recorded.

Resorptions were classified as early or late. Early resorptions included a conceptus characterized by a grossly necrotic mass that had no recognizable fetal form or presence of nidation sites (“pregnant by stain”). Late resorptions were characterized by grossly necrotic but recognizable fetal form with placental remnants visible.^57,58^ Postimplantation loss was calculated as the number of dead plus resorbed conceptuses divided by the total number of implantations (multiplied by 100). For each uterus with no macroscopic evidence of implantation, the uterus was stained with 10% (v/v) ammonium sulfide to visualize any possible early implantation sites.^59^

Adult females that were euthanized moribund, delivered early, or found dead received a gross necropsy that included an examination of the thoracic and abdominal viscera for evidence of dosing trauma or toxicity. The uterus of each female was examined and stained, if necessary, to determine pregnancy status. Females were not retained for further examination.

All rabbits that aborted (defined as delivering before GD 29), were euthanized moribund, or found dead received a gross necropsy that included examination of the thoracic and abdominal viscera for evidence of dosing trauma, toxicity, and gross lesions. The uterus of each female was examined and stained, as necessary, to determine pregnancy status. Females were not retained for further examination.

### Dose Range-finding Study in Rats

Time-mated rats were individually identified by tail marking and randomized by GD 3 body weight stratification into six groups (vehicle control, low, low-mid, mid, mid-high, or high) using Southern Research’s Instem™ Provantis^®^ (version 8) electronic data collection system.

Groups of 10 time-mated female rats were administered 0 (vehicle control), 20, 40, 80, 160, or 320 mg vinpocetine/kg body weight/day (mg/kg/day), calculated from the most recent body weight, in 0.5% aqueous methylcellulose by gavage from GD 6 to GD 20. Vehicle control animals received aqueous methylcellulose alone; the dosing volume was 5 mL/kg/day. Given the limited data in one publication and potential strain differences, the high dose of 320 mg/kg was chosen to ensure that the animals were sufficiently challenged even though excessive maternal toxicity might result. Data from this study were used to inform the prenatal developmental toxicity study.

On GD 21, rat fetuses were removed from the uterus, individually weighed (live fetuses only), and examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were euthanized by decapitation or with intraperitoneal injection of a commercially available solution containing sodium pentobarbital followed by bilateral pneumothorax or decapitation. Fetuses were not retained following completion of the external examination.

### Prenatal Developmental Toxicity Study in Rats

On receipt (GD 1 or 2), time-mated rats were individually identified by tail marking and were randomized by GD 3 body weight stratification into four groups (vehicle control, low, mid, or high) using Southern Research’s Instem™ Provantis^®^ (version 9) electronic data collection system. Dams were received over a 4-day period to allow for a staggered study start.

Groups of 25 time-mated female rats were administered 0 (vehicle control), 5, 20, or 60 mg vinpocetine/kg/day, calculated from the most recent body weight, in 0.5% aqueous methylcellulose by gavage from GD 6 to GD 20 (15 days). Vehicle control animals received the aqueous methylcellulose vehicle alone; the dosing volume was 5 mL/kg.

On GD 21, fetuses were removed from the uterus, and live fetuses individually weighed. The uteri of animals that did not appear pregnant were examined for nidations (implantation sites) by staining with 0.5% ammonium sulfide.^59,60^ All fetuses were examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were subsequently euthanized by intraperitoneal injection of sodium pentobarbital. Fetal sex was confirmed by inspection of gonads in situ. All fetuses were examined for soft tissue alterations under a stereomicroscope.^61,62^ The heads were removed from approximately half of the fetuses in each litter and fixed in Bouin’s solution and subsequently examined by free-hand sectioning.^63^ This technique precludes skeletal evaluations of the skull; therefore, remaining heads and all fetuses were eviscerated, fixed in ethanol, macerated in potassium hydroxide, stained with alcian blue and alizarin red, and examined for subsequent cartilage and osseous alterations.^60,64^ External, visceral, and skeletal fetal alterations were recorded as developmental variations or malformations.

### Dose Range-finding Study in Rabbits

Groups of eight time-mated female rabbits were administered 0 (vehicle control), 25, 75, 150, or 300 mg vinpocetine/kg/day (based on the most recent body weight) in 0.5% aqueous methylcellulose by gavage from GD 7 to GD 28. Vehicle control animals received aqueous methylcellulose alone; the dosing volume was 5 mL/kg. The high dose of 300 mg/kg was chosen informed by data from the rat range-finding study and the limited toxicokinetic data in the literature on rabbits, suggesting similar disposition of vinpocetine between rats and rabbits.^27,28,30,33-35^

On GD 29, fetuses were removed from the uterus, individually weighed (live fetuses only), and examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were euthanized by intraperitoneal injection of a commercially available solution containing sodium pentobarbital. Fetuses were not retained following completion of the external examination.

## Statistical Methods

In the dose range-finding studies and the prenatal developmental toxicity study, statistical analyses were performed on data from pregnant females that survived until the end of the study and were examined on GD 21 (rats) or GD 29 (rabbits) and from live fetuses. Statistical analyses were performed using SAS 9.3 (SAS Institute, Cary NC).

### Descriptive Statistics

Maternal Parameters: Maternal body weights were measured daily starting at GD 3 and reported as means. Terminal maternal body weights at GD 21 (rats) or GD 29 (rabbits) were adjusted for gravid uterine weight by subtracting the gravid uterine weight from the female’s body weight. Body weight gains were calculated over each 3-day interval and from GD 6 to GD 21 (rats) or GD 29 (rabbits). Daily feed consumption was averaged over each 3-day interval and from GD 6 to GD 21 (rats) or GD 29 (rabbits). These continuous variables, in addition to gravid uterine weights and other organ weights, hematology, and clinical chemistry were summarized with means and standard errors.

Placental and Fetal Parameters: Data on uterine contents are reported as means and standard errors of counts per dam/litter (corpora lutea, implants, resorptions, dead fetuses) and as total numbers of occurrences (resorptions, dead fetuses). Data from females that were not pregnant or that did not survive to the end of the study were not included. Postimplantation loss is calculated as a percentage of the number of implants per dam. Fetal findings are reported as means and standard errors of counts per litter (numbers of live fetuses, male fetuses, female fetuses), means and standard errors of litter means (fetal weight, male fetal weight, female fetal weight), and total numbers of occurrences (total number of live fetuses). In addition, several calculated variables are reported, including the percentage of live male fetuses per litter.

Incidences of morphological findings from the gross, external, visceral, skeletal and head examinations of pathology of placentae and fetuses are presented as number and percentage of affected fetuses and as number and percentage of affected litters.

### Analysis of Maternal Parameters and Uterine Contents

Maternal organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^65^ and Williams.^66,67^ Non-normally distributed variables, such as food consumption, hematology, clinical chemistry, and uterine content endpoints, were analyzed using the nonparametric multiple comparison methods of Shirley^68^ (as modified by Williams^69^) and Dunn.^70^ For normally distributed and non-normally distributed variables, the Jonckheere test^71^ was used to assess the significance of dose-related trends at p < 0.01 to determine whether a monotonic trend-sensitive test (the Williams or Shirley test) was more appropriate than a test that does not assume a monotonic dose-related trend (the Dunnett or Dunn test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^72^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

Fetal body weights were analyzed using mixed-effects linear models, with litter as a random effect to account for potential within-litter correlations. To test for a linear trend, dose was entered into the model as its numeric value and its significance was evaluated. For pairwise comparisons with the control group, a second mixed-effects model with dose entered into the model as a categorical variable was estimated, followed by the Dunnett^65^ and Hsu^73^ multiple comparisons tests.

### Analysis of Incidences of Gross Pathology and Morphology Findings

Incidences of gross findings, malformations, and variations in the fetuses were summarized and analyzed as the number of litters affected and as the number of fetuses affected. Incidences of gross findings, malformations, and numbers of litters affected were analyzed using the Cochran-Armitage trend test^74^ and the Fisher exact test.^75^ The numbers of fetuses affected were analyzed using mixed-effects logistic regression in which the litter was a random effect to account for potential litter effects.^76-78^ For each fetal finding, an initial mixed-effects logistic regression model used the numeric value of dose to assess the significance of a dose-related trend; a subsequent logistic regression model incorporated dose as a categorical variable to compare each dose group to the control group. To conduct the mixed-effects logistic regression analyses, at least one finding was required per dose group, and the correlation matrix describing the relationship between litters was required to be “positive definite.” If the mixed-effects logistic regression failed to converge or did not meet the specified criteria, two separate analyses were used to bracket the true P value. The Cochran-Armitage trend test and the Fisher exact test were used with the litter as the experimental unit to calculate the upper limit for the true p value and with the fetus as the experimental unit to calculate the lower limit for the true p value.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP developmental and reproductive toxicity studies. However, historical control data are often helpful in interpreting potential exposure-related effects, particularly for uncommon fetal findings that occur at a very low incidence. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Factors that could affect the background incidences of fetal findings at a variety of anatomical sites are diet, sex, strain/stock, route of exposure, study type, and laboratory that conducted the study. The NTP historical control database for teratology studies contains all fetal evaluations (e.g., teratology studies or modified one-generation studies) for each laboratory. In general, the historical control database for a given study includes studies using the same route of administration and study design. Historical control data for rats in this Developmental and Reproductive Toxicity Technical Report represents data from gavage studies conducted at Southern Research Institute. The concurrent controls are included in the historical control data set. NTP historical control data are available online at https://ntp.niehs.nih.gov/go/historical_controls.

## Quality Assurance Methods

The dose range-finding and prenatal developmental toxicity studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). Records from these studies were submitted to the NTP Archives. The prenatal developmental toxicity study was audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the final study data tables for the dose range-finding and prenatal developmental toxicity studies and a draft of this NTP Developmental and Reproductive Toxicity Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.