# Introduction

Figure 1

Vinpocetine (CASRN 42971-09-5; Chemical Formula: C_22_H_26_N_2_O_2_; Molecular Weight: 350.46)

Synonyms: Apovincaminic acid ethyl ester; cis-apovincaminic acid ethyl ester; ethyl (+)-apovincaminate; ethyl apovincamin-22-oate; ethyl (+)-cis-apovincaminate; ethyl (3α,16α)-eburnamenine-14-carboxylate.

Trade names: Bravinton, Cavinton, Ceractin, Intelectol, RGH-4405, TCV-3B, Vinporal.

## Chemical and Physical Properties

Vinpocetine is a white crystalline solid with a molecular mass of 350.45 g/mol. It has an estimated boiling point of 420°C, melting point of 147–153°C, a log K_OW_ of 4.3^1^ and vapor pressure of 3.02 × 10^−7^ mm Hg at 25°C.

## Production, Use, and Human Exposure

Vinpocetine can be synthesized in several ways from vincamine, an alkaloid extract from the periwinkle plant. One method described by Szabó et al.^2^ involves heating (+)-14-oxo-15-hydroxyimino-E-homo-eburnane with ethanol and sulfuric acid. The resulting solution is cooled and brought to a pH of 9 with ammonium hydroxide. The organic phase is extracted with methylene chloride, then dried, filtered, and evaporated. The residual oil is recrystallized in ethanol, which yields 67.6% vinpocetine. A “one-pot” synthesis method describes two synthesis pathways for vinpocetine production from vincamine.^3^ With this method, vinpocetine is produced (80% product yield) through either transesterification or dehydration of vincamine in ethanol using Lewis acids; ferric chloride catalyzed both processes. Tabersonine, an alkaloid extract from voacanga seeds found mostly in West Africa, can also serve as a source from which vinpocetine can be derived.^4^ Additionally, there are patents for synthetic methods of vinpocetine production that can result in higher yields (~90%) than the semisynthetic methods described above. For example, one method described the reaction of apovincaminic acid with ethanol in the presence of 2-fluoro-1,3,5-trinitrobenzene and 4-dimethylaminopyridine.^5^

Since the late 1970s, vinpocetine has been widely available as a pharmaceutical agent in Hungary, Germany, Poland, Russia, China, and Japan for use in cerebrovascular and cognitive disorders.^6^ In the United States, vinpocetine is mainly marketed as a dietary supplement with the primary purported indication of cognitive enhancement, including use for Alzheimer’s, dementia, and ischemic stroke.^6-11^ Though original indications for vinpocetine promoted its use in the elderly, several products are currently available that are specifically marketed toward students as brain supplements for increasing cognitive performance.^12^ Additionally, vinpocetine is used among healthy athletes within the bodybuilding community for reported enhancement of visual acuity, memory, and focus in addition to rapid reductions in body fat.^13^ Other reported uses are for vertigo, urinary incontinence, tinnitus, Meniere’s disease, visual impairment, menopause symptoms, chronic fatigue syndrome, seizure disorders, and prevention of motion sickness.^14-18^ Several patents claim additional applications for vinpocetine, including topical use for enhanced female sexual response,^19,20^ as a primary ingredient in a supplement for the improvement of sleep and lucid dreaming,^21^ and as an ingredient (either alone or in combination with stimulants, anti-motion drugs, or nootropics) for intranasal administration to treat dyslexia in children.^22^

Human exposure to vinpocetine typically occurs through oral consumption. As reported by the Physicians’ Desk Reference for Nutritional Supplements, vinpocetine doses can range from 5 to 20 mg per day.^23^ In the United States, vinpocetine products are available in dosages ranging from 5 to 30 mg, with recommended uses of one to three times daily, equaling daily doses of 5 to 90 mg. However, a recent analysis of vinpocetine supplements demonstrated a common problem with botanical dietary supplements, where 6 of the 23 (17%) sampled supplements contained no vinpocetine and, in those that did contain vinpocetine, the actual vinpocetine content varied from what was stated on the label.^24^ Thus, actual daily consumption rates could differ from the target dose and potentially be higher than recommended by the product labels.

## Regulatory Status

Vinpocetine is often marketed as a dietary supplement in the United States and, therefore, regulated by the Food and Drug Administration (FDA) under the Dietary Supplement Health and Education Act of 1994. Vinpocetine was submitted in several notifications to the FDA as a new dietary ingredient by manufacturers beginning in 1997. However, the FDA has recently published a notice in the Federal Register requesting comment as to the regulatory status of vinpocetine as a dietary ingredient. Specifically, FDA tentatively concluded that vinpocetine does not meet the definition of a dietary ingredient and is excluded from the definition of a dietary supplement in the Food, Drug, and Cosmetic Act.^25^ This administrative proceeding has not been finalized.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

In rats, vinpocetine was rapidly absorbed following a single oral administration with peak plasma and tissue concentrations occurring within 2 hours.^26-28^ Following administration of [3H]vinpocetine, approximately 47% and 34% of the dose was recovered in the urine and feces, respectively, at 48 hours; less than 5% was recovered in bile within 9 hours of administration.^29^ The highest radioactivity was recovered in the liver and small intestine, followed by the lung, stomach, kidney, and adrenal glands. Except for the liver and kidneys, residual radioactivity in tissues returned to minimal levels within 48 hours of administration. Urinary and fecal excretion of vinpocetine were similar, following a 5-day repeated oral exposure. The plasma elimination half-life of vinpocetine after a single gavage administration of 10 mg^30^ or 1–2 mg/kg^27,28^ was ≤3 hours. The maximum plasma concentration (C_max_) and area under the concentration-versus-time curve (AUC) after a single gavage administration of 2 mg/kg were 135.33 ng/mL and 504.03 ng.h/mL,^28^ respectively; after 1 mg/kg gavage, the C_max_ and AUC were 23.8 ng/mL and 57.4 ng.h/mL,^31^ respectively. Oral bioavailability of vinpocetine in rats was 52%, suggesting extensive first pass metabolism.^30^ The main metabolite of vinpocetine identified in rat urine was apovincaminic acid (approximately 75% of urinary excretion), arising from de-esterification of vinpocetine.^29,30^ Formation of apovincaminic acid following oral administration of vinpocetine in rats was rapid, with the highest plasma concentration observed approximately 1 hour after administration with an elimination half-life of 3–10 hours.^27,30^

The National Toxicology Program (NTP) conducted a study to investigate the toxicokinetics of vinpocetine and apovincaminic acid in pregnant rats and to estimate gestational transfer following gavage administration of 5 and 20 mg/kg vinpocetine to dams from gestational days (GD) 6 through GD 18.^32^ Both vinpocetine and apovincaminic acid were detected in dam plasma. Vinpocetine was absorbed rapidly in dams with the C_max_ occurring ≤1.4 hours after dosing. The predicted C_max_ and AUC increased less than proportionally to the dose. Vinpocetine was rapidly distributed to the peripheral compartment. More importantly, a significant transfer of vinpocetine from dams to fetuses was observed with fetal C_max_ and AUC ≥55% of that of dams. Vinpocetine was rapidly cleared from dam plasma with a half-life of ≤4.02 hours with no apparent dose-related effect. Vinpocetine was rapidly and highly metabolized to apovincaminic acid with apovincaminic acid C_max_ reached ≤1.5 hours. The C_max_ and AUC values indicate that the apovincaminic acid levels were ≥2.7-fold higher than vinpocetine levels in dams, although in the fetuses, apovincaminic acid levels were much lower than those of vinpocetine.

Absorption of vinpocetine was also rapid in New Zealand White rabbits following oral administration, with peak plasma concentration reached within 2 hours; maximum plasma concentrations varied with 209 ng/mL, 163 ng/mL, and 61.5 ng/mL reported for 10 mg, 10 mg/kg, and 40 mg, respectively.^33-35^ The plasma elimination half-life was 2–6.5 hours, depending on the study. In dogs, the elimination half-life was longer (approximately 9 hours).^26^

NTP investigated systemic exposure to vinpocetine and apovincaminic acid in pregnant New Zealand White rabbits, using plasma samples collected in the current study. Doses of 0, 20, 40, 80, 160, or 320 mg/kg vinpocetine were administered by gavage from GD 7 through GD 19, and doe plasma was collected 1 and 2 hours following the last dose.^36^ Vinpocetine and apovincaminic acid were detected at both time points, and the concentrations of both increased less than proportionally to the dose. Unlike in rats, the plasma concentration of apovincaminic acid was much higher than that of vinpocetine, suggesting significant species difference in metabolism, which is a conclusion reached in previous metabolism studies, both in vivo^26^ and in vitro.^37^ In addition to apovincaminic acid, hydroxyvinpocetine, hydroxyl-apovincaminic acid, and dihydroxy-vinpocetine-glycinate are other minor metabolites that have been identified in dogs and humans.^26^

### Humans

In humans, similar to animals, absorption of vinpocetine following ingestion was fast with a maximum plasma concentration reached within 2 hours after ingestion and a plasma elimination half-life of ≤2 hours.^38-42^ The reported oral bioavailability in humans varies from 6.7% to 57%.^38,39^ Vinpocetine bioavailability differs if administered with or without food: relative bioavailability was 60–100% higher in individuals who were administered vinpocetine under non-fasting conditions compared with fasting conditions.^41^ In the same study, food intake did not affect the rate of absorption, with maximum serum concentrations observed at 1 hour following vinpocetine administration, similar to other observed peak plasma levels. Gulyás et al.^43,44^ examined the tissue distribution of orally administered ^11^C-vinpocetine in humans through the use of positron emission tomography and found that vinpocetine rapidly enters the blood stream and liver through the stomach and gastrointestinal tract. These studies also demonstrated radioactivity uptake and distribution of vinpocetine in the brain, indicating that the compound can cross the blood brain barrier.

Metabolism of vinpocetine is extensive in humans similar to animals, with undetectable levels of unchanged vinpocetine in the urine 24 hours after administration.^38^ In vitro studies with human hepatocytes have demonstrated that human metabolism of vinpocetine is similar to that in dogs, in that metabolism occurs almost exclusively in the liver.^37^ The main metabolite measured in humans is apovincaminic acid.^40,45,46^

## Developmental and Reproductive Toxicity

### Experimental Animals

Data in the publicly available literature regarding the developmental and reproductive toxicity of vinpocetine are limited to one publication that summarized 14 safety studies.^47^ Vinpocetine was tested in multiple animal species (rats, dogs, and rabbits) at doses ranging from 2 to 150 mg/kg, depending on the route of exposure (oral, intraperitoneal, intravenous, or intramuscular). Maternal findings observed in these studies were limited to decreased maternal body weight gain and uterine bleeding. Fetal findings ranged from no adverse fetal outcomes (noted in the litters that survived to term) to fetal growth retardation and malformations; however, few details were reported on the types of malformations. Fetal loss, including whole litter resorptions, was noted in all studies. The publication included few study findings and details were minimal, but the authors concluded, on the basis of the data presented, that vinpocetine was safe for use in adults but recommended avoidance for pregnant women.

### Humans

No studies examined vinpocetine exposure and adverse reproductive (or prenatal) outcomes in humans in the literature.

## General Toxicity

### Experimental Animals

The oral LD_50_ (lethal dose for 50% of exposed animals) value for vinpocetine is approximately 500 mg/kg in rats and mice, the intravenous LD_50_ is approximately 50 mg/kg in rats and mice, and the intraperitoneal LD_50_ ranges from 134 to 240 mg/kg in rats and mice.^47,48^ Rodents that were administered lethal doses displayed the clinical observations of ataxia and clonic convulsions.^47^

Summary data from subchronic toxicity tests of vinpocetine in animals were published with limited details by Cholnoky and Dömök.^47^ Rats exposed orally to 100 mg/kg/day for 4 weeks displayed increased liver and thyroid gland weights and clinical observations of increased salivation. Contrary to these findings, no vinpocetine-related toxicity was noted in a separate rat study with doses up to 100 mg/kg by oral gavage. A 3-month intraperitoneal injection study in rats resulted in mortality (38% of the males, 25% of the females) due to severe confluent fibroblastic peritonitis and ascites with vinpocetine doses of 25 mg/kg/day. No general toxicities were noted in a study performed in dogs with vinpocetine doses up to 25 mg/kg/day administered orally through capsules for six months.

### Humans

Vinpocetine exposure in humans has been associated with nausea, dizziness, insomnia, drowsiness, dry mouth, transient hypotension and tachycardia, pressure-type headache, and facial flushing.^23,49^ Long-term use of vinpocetine has also been associated with slight reductions in systolic and diastolic blood pressure, as well as slight reductions in blood glucose.^23^

## Genetic Toxicity

No studies on the genetic toxicity of vinpocetine were found in the published literature. However, the NTP conducted a bacterial mutation assay with vinpocetine, which produced negative results in all three bacterial strains tested, and a combined in vivo micronucleus/comet assay in female mice. Results of the micronucleus test were negative, and results of the comet assay, which evaluates potential for DNA damage, were judged to be equivocal in liver and negative in blood leukocytes and stomach epithelial cells. Results of an in vitro micronucleus test with vinpocetine in TK6 cells were judged to be positive. Data from all NTP genetic toxicity tests with vinpocetine are available in the NTP Chemical Effects in Biological Systems database: https://doi.org/10.22427/NTP-DATA-002-03277-0000-0000-1.^50^

## Study Rationale

The dietary supplement vincamine was nominated by the National Cancer Institute for genotoxicity, subchronic toxicity, and toxicokinetic studies due to a lack of information on potential toxicity. However, vincamine is no longer widely marketed as a dietary supplement in the United States and has been replaced by its semisynthetic derivative, vinpocetine. Due to limited literature indicating that vinpocetine might not be safe for use during pregnancy and the possibility for widespread exposure to women of childbearing age, the developmental toxicity of vinpocetine in rats was investigated. Given the adverse responses on prenatal development that were observed in the rat, a dose range-finding rabbit study was included to provide information on vinpocetine in a second species and to assess species-specific developmental effects.