# Appendix C Sentinel Animal Program

## C.1 Methods

Animals used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of animals is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Ten New Zealand White rabbits were maintained for the dose range-finding rabbit study. Blood samples were collected and allowed to clot, and the serum was separated. All samples were processed appropriately and testing performed by IDEXX BioResearch [formerly Research Animal Diagnostic Laboratory (RADIL), University of Missouri (Columbia, MO)] for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the study are also listed.

Table C-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Multiplex Fluorescent Immunoassay
CAR bacillus | Study termination
Clostridium piliform | Study termination
Encephalitozoon cuniculi | Study termination
Rotavirus | Study termination
Immunofluorescence Assay | Study termination
Treponema | Study termination

## C.2 Results

Antibodies to Rotavirus were detected in several samples. Rotavirus is a common virus in rabbits, and the laboratory determined that it did not affect the study. All other test results were negative.