# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 Vinpocetine

Vinpocetine was obtained from Maypro Industries, LLC (Purchase, NY) in one lot (VA201211001) that was used in the dose range-finding studies in rats and rabbits and the prenatal developmental toxicity gavage study in rats. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH) for the study laboratory at Southern Research (Birmingham, AL). Reports on analyses performed in support of the vinpocetine studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot VA201211001 of the chemical, a white crystalline powder, was identified as vinpocetine using Fourier transform infrared (FTIR) spectroscopy, proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy, and gas chromatography (GC) with mass spectrometry detection. The optical activity analysis indicated an average rotation of +131.6°, which is consistent with the optical rotation of vinpocetine. FTIR spectra were consistent with a literature spectrum^100^ and the structure of vinpocetine. The proton and carbon-13 NMR spectra were consistent with those expected for the proposed structure of vinpocetine and with the ACD-predicted (Advanced Chemistry Development) spectra. Representative FTIR and proton NMR spectra are presented in Figure A-1 and Figure A-2, respectively. The mass spectrum of the major peak from the gas chromatographic analysis was consistent with the identity of vinpocetine; a single impurity observed in this analysis was tentatively identified as apovincamine, a structurally similar compound. Optical activity analysis of the bulk chemical conducted by Exova (Santa Fe Springs, CA) indicated an average rotation of +131.6°, consistent with the rotation range specified by the manufacturer.

Karl Fischer titration and elemental analyses of lot VA201211001 were conducted by Galbraith Laboratories, Inc. (Knoxville, TN). Additional elemental analyses (72 elements; sodium through uranium) were conducted by Elemental Analysis, Inc. (Lexington, KY) using proton-induced X-ray emission (PIXE) spectroscopy. The purity of the test chemical was determined using melting point analysis conducted on a Perkin-Elmer (Shelton, CT) Diamond differential scanning calorimetry (DSC) instrument scanning from 140°C to 152°C at a rate of 1°C per minute. Purity profiles were obtained using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection and GC with flame ionization detection (FID) by system A (Table A-1). The HPLC system included an Agilent 1100 instrument (Agilent, Santa Clara, CA), a C_18_, 250 mm × 4.6 mm, 4 µm particle size column (Phenomenex, Torrance, CA), mobile phases (A) 10:90 (v:v) methanol:0.05 M ammonium acetate (pH 8.0) and (B) 90:10 (v:v) methanol:0.05 M ammonium acetate (pH 8.0), an isocratic gradient of 10% A and 90% B, UV detection at 230 nm, and a flow rate of 0.75 mL/minute. Screening for selected volatiles in the test chemical was performed using standard addition with authentic standards of non-halogenated (hexane, benzene, diethyl ether, acetone, 1,4-dioxane, and toluene), and halogenated (chloroform, carbon tetrachloride, trichloroethylene, and methylene chloride) volatile compounds using headspace GC/FID by system B.

Karl Fischer titration indicated less than 0.07% water. For lot VA201211001, elemental analyses for carbon, hydrogen, nitrogen, and oxygen agreed with the theoretical values for vinpocetine; PIXE analyses indicated no inorganic impurities greater than 0.1%. Melting point analysis by DSC averaged 149.88°C, which is consistent with a literature reference range (147°C to 153°C^101^) and differential scanning calorimetry indicated a purity of 99.9%. HPLC/UV indicated one major peak (99.5% of the total peak area) and two impurities greater than 0.1% of the total peak area (0.17% and 0.28%). By comparison to retention times of authentic standards of structurally similar compounds, the larger impurity peak was tentatively identified as apovincamine. GC/FID indicated one major peak (99.3% of the total peak area) and one reportable impurity (0.67% of the total peak area); retention time comparison indicated tentative identification of this impurity as apovincamine. Screening for volatiles indicated the presence of 0.018% methylene chloride. The overall purity of lot VA201211001 was determined to be greater than 99.3%.

Stability studies of the bulk chemical were performed using GC/FID by system A. These studies indicated that vinpocetine was stable as a bulk chemical for at least 14 days when stored in sealed amber glass vials at temperatures up to 60°C. To ensure stability, the bulk chemical was stored by the analytical chemistry laboratory at room temperature in sealed double plastic bags in a plastic bucket. Reanalysis of the bulk chemical was performed twice by the analytical chemistry laboratory during the studies with GC/FID by system C and no degradation of the bulk chemical was detected.

### A.1.2 Methylcellulose

Methylcellulose was obtained from Spectrum Chemical Manufacturing Corporation (Gardena, CA) in two lots (2CB0045 and 2DH0326); lot 2CB0045 was used in the dose range-finding study in rats, and lot 2DH0326 was used in the prenatal developmental toxicity study in rats and the dose range-finding study in rabbits. Lots 2DH0326 and 2CB0045 were identified by the analytical chemistry laboratory as methylcellulose using FTIR spectroscopy; sample spectra were in good agreement with the structure of methylcellulose and a literature reference^102^ and cited absorptions were consistent with the structure of methylcellulose.^103^ The methoxy content of lots 2DH0326 and 2CB0045 were determined by Galbraith Laboratories, Inc.; the results of duplicate determinations for methoxy group content were within the acceptance limits of 26.0% to 33.0%.

## A.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared once for each study by mixing vinpocetine with 0.5% aqueous methylcellulose solution to give the required concentrations (Table A-2). The dose formulations were stored at room temperature in clear glass bottles with Teflon^®^-lined lids in sealed amber plastic bags for up to 38 days.

The analytical chemistry laboratory performed homogeneity studies of 0.1 and 200 mg/mL formulations, syringeability studies for 18- and 22-gauge gavage needles using the 200 mg/mL formulation, resuspendability studies of the 200 mg/mL formulation, and stability studies of the 0.1 mg/mL formulation; all of these analyses were conducted using GC/FID by system D (Table A-1). Homogeneity, syringeability, and resuspendability were confirmed, and stability was confirmed for at least 42 days for dose formulations stored in clear glass bottles with Teflon^®^-lined lids packaged in sealed amber plastic bags at room temperature and for 3 hours under simulated animal room conditions (Table A-2).

Periodic analyses of the dose formulations of vinpocetine were conducted by the analytical chemistry laboratory using GC/FID by system D. During the dose range-finding study in rats, the dose formulations were analyzed once; all five dose formulations analyzed and used were within 10% of the target concentrations (Table A-3). Animal room samples of these dose formulations were also analyzed; four of five were within 10% of the target concentrations. During the prenatal developmental toxicity study in rats, the dose formulations were analyzed once; animal room samples of these dose formulations were also analyzed (Table A-4). All three dose formulations and all three animal room samples were within 10% of the target concentrations. During the dose range-finding study in rabbits, the dose formulations were analyzed once (Table A-5). Of the dose formulations analyzed during the study, all eight were within 10% of the target concentrations; two of four animal room samples were within 10% of the target concentrations.

Table A-1 Gas Chromatography Systems Used in the Gavage Studies of Vinpocetine^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame Ionization | Rtx^®^-5, 30 m × 0.32 mm, 0.5 µm film (Restek, Bellefonte, PA) | Helium at ~2 mL/minute | 100°C to 150°C at 10°C/minute, then 15°C/minute to 300°C, held for 15 minutes
System B
Flame Ionization | Rtx^®^-624, 30 m × 0.53 mm, 3.0 µm film (Restek) | Helium at ~5 mL/minute | 35°C for 14 minutes, then 15°C/minute to 40°C, held for 3 minutes, then 15°C/minute to 240°C, held for 2 minutes
System C
Flame Ionization | ZB-5, 30 m × 0.32 mm, 0.25 µm film (Phenomenex, Torrance, CA) | Helium at ~2 mL/minute | 100°C to 150°C at 10°C/minute, then 15°C/minute to 300°C, held for 15 minutes
System D
Flame Ionization | Rtx^®^-5, 30 m × 0.32 mm, 0.5 µm film (Restek) | Helium at ~2 mL/minute | 120°C to 150°C at 10°C/minute, then 15°C/minute to 300°C, held for 15 minutes

^a^ The gas chromatographs were manufactured by Agilent Technologies, Inc. (Santa Clara, CA).

Table A-2 Preparation and Storage of Dose Formulations in the Gavage Studies of Vinpocetine in Rats and Rabbits

Dose Range-Finding and Prenatal Developmental Toxicity Studies
Preparation
The dosing vehicle was prepared by mixing methylcellulose with heated, deionized water while stirring and then diluting with water to form a 0.5% solution, which was allowed to cool. The formulations were prepared by adding the appropriate amount of vinpocetine to a small amount of the vehicle in a mixing container and stirring manually to form a paste. The formulations were diluted to 90% of the final volume with vehicle and stirred with a Silverson mixer (Silverson Machines, Inc., East Longmeadow, MA) at approximately 4,500 rpm for approximately 10 minutes. Formulations were then diluted to final volume with vehicle and stirred with a stir bar on a stir plate with a vigorous vortex for approximately 2 minutes. The dose formulations were prepared once for each study.
Chemical Lot Number
VA201211001
Maximum Storage Time
Up to 42 days (dose range-finding study in rats) Up to 42 days (prenatal developmental toxicity study in rats) Up to 42 days (dose range-finding study in rabbits)
Storage Conditions
Stored in clear glass bottles with Teflon®-lined lids in sealed amber plastic bags at room temperature
Study Laboratory
Southern Research (Birmingham, AL)

Table A-3 Results of Analyses of Dose Formulations Administered to Female Rats in the Dose Range-finding Gavage Study of Vinpocetine

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
February 10-14, 2014 | February 12, 2014 | 4 | 4.22^b^ | +6
| | 8 | 8.44 | +6
| | 16 | 16.3 | +2
| | 32 | 31.5^c^ | −2
| | 64 | 67.1^b^ | +5
| March 19, 2014^d^ | 4 | 4.29 | +7
| | 8 | 7.59 | −5
| | 16 | 15.2 | −5
| | 32 | 32.8 | +3
| | 64 | 55.2 | −14

^a^ Results of triplicate analyses except as noted. Dosing volume = 5 mL/kg; 4 mg/mL = 20 mg/kg, 8 mg/mL = 40 mg/kg, 16 mg/mL = 80 mg/kg, 32 mg/mL = 160 mg/kg, and 64 mg/mL = 320 mg/kg.

^b^ Nine replicates were analyzed.

^c^ Five replicates were analyzed.

^d^ Animal room samples.

Table A-4 Results of Analyses of Dose Formulations Administered to Female Rats in the Prenatal Developmental Toxicity Gavage Study of Vinpocetine

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
January 5, 2015 | January 8–9, 2015 | 1 | 0.962^b^ | −4
| | 4 | 4.03 | +1
| | 12 | 11.6^b^ | −3
| February 5–6, 2015^c^ | 1 | 0.970 | −3
| | 4 | 3.98 | −1
| | 12 | 11.8 | −2

^a^ Results of triplicate analyses except as noted. Dosing volume = 5 mL/kg; 1 mg/mL = 5 mg/kg, 4 mg/mL = 20 mg/kg, and 12 mg/mL = 60 mg/kg.

^b^ Nine replicates were analyzed.

^c^ Animal room samples.

Table A-5 Results of Analyses of Dose Formulations Administered to Female Rabbits in the Dose Range-finding Gavage Study of Vinpocetine

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
April 13, 2015 | April 14–16, 2015 | 5 | 5.02^b^ | 0
| | 5 | 5.07 | +1
| | 15 | 14.9 | −1
| | 15 | 15.0 | 0
| | 30 | 30.2 | +1
| | 30 | 30.3 | +1
| | 60 | 57.4 | −4
| | 60 | 61.2^b^ | +2
| May 27–28, 2015^c^ | 5 | 5.84 | +17^d^
| | 15 | 28.0 | +87^d^
| | 30 | 29.9 | 0
| | 60 | 59.1 | −2

^a^ Results of triplicate analyses except as noted. Dosing volume = 5 mL/kg; 5 mg/mL = 25 mg/kg, 15 mg/mL = 75 mg/kg, 30 mg/mL = 150 mg/kg, and 60 mg/mL = 300 mg/kg.

^b^ Nine replicates were analyzed.

^c^ Animal room samples.

^d^ High results believed to be caused by an inability to aliquot a representative sample for analysis due to small volumes remaining.

Figure A-1

Fourier Transform Infrared Absorption Spectrum of Vinpocetine

Figure A-2

Proton Nuclear Magnetic Resonance Spectrum of Vinpocetine