# Overview

The Centers for Disease Control and Prevention and the Agency for Toxic Substances and Disease Registry nominated chemicals associated with the 2014 Elk River spill in West Virginia to the National Toxicology Program (NTP) for toxicology studies. In response, NTP performed research to evaluate the toxicity of 4-methylcyclohexanemethanol and the additional chemical components of crude 4-methylcyclohexanemethanol through various short-term studies. The goals of this research program were to: (1) evaluate the teratogenic, immunotoxic, and genotoxic potential of 4-methylcyclohexanemethanol; (2) identify sensitive biological effects of the spill chemicals and provide additional information about the levels at which there are no adverse effects; and (3) use efficient medium- and high-throughput methods to predict qualitative and quantitative toxicological properties of all chemicals spilled into the Elk River.

These goals were addressed using guideline prenatal developmental toxicity studies in rats, dermal irritation and hypersensitivity studies in mice, short-term toxicogenomic studies in rats, medium-throughput screening assessments in lower animal models, and cell-based high-throughput screening assays. The information and results presented in this report on developmental and reproductive toxicity are specific to the prenatal developmental toxicity studies on 4-methylcyclohexanemethanol; however, further information about the NTP research program related to the Elk River spill in West Virginia is available at https://ntp.niehs.nih.gov/go/wvspill.