# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2690-2052

DOI: https://doi.org/10.22427/NTP-DART-02

Report Series: NTP Developmental and Reproductive Toxicity Report Series

Report Series Number: 02

Official citation: National Toxicology Program (NTP). 2020. NTP developmental and reproductive toxicity technical report on the prenatal development studies of 4-methylcyclohexanemethanol (CASRN 34885-03-5) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (gavage studies). Research Triangle Park, NC: National Toxicology Program. DART Report 02.