# Peer Review

An external ad hoc panel was convened at the National Institute of Environmental Health Sciences, Research Triangle Park, NC on July 31, 2019, to peer review the draft NTP Developmental and Reproductive Toxicity Technical Report on the Prenatal Development Studies of 4-Methylcyclohexanemethanol (CASRN 34885-03-5) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats (Gavage Studies). The public could view the proceedings via webcast and there was opportunity for presentation of oral public comment. The selection of panel members and conduct of the peer review were in accordance with Federal policies and regulations. The panel was charged to:

1. Review and evaluate the scientific and technical elements of each study and its presentation.
2. Determine whether each study’s experimental design, conduct, and findings support the NTP’s conclusion regarding the prenatal developmental toxicity of the substance tested.

NTP carefully considered the panel’s recommendations in finalizing the technical report. The peer review report is provided in Appendix C. Other meeting materials are available on the NTP website (https://ntp.niehs.nih.gov/go/meeting).

## Peer Reviewers

- George Daston, Ph.D., Chairperson
  The Procter and Gamble Company
  Cincinnati, Ohio, USA
- Cheryl Broussard, Ph.D.
  Centers for Disease Control and Prevention
  Atlanta, Georgia, USA
- Alan Hoberman, Ph.D.
  Charles River Laboratories Preclinical Services
  Horsham, Pennsylvania, USA
- Linda Roberts, Ph.D.
  NapaTox Consulting LLC
  San Francisco, California, USA
- Mary Alice Smith, Ph.D.
  University of Georgia
  Athens, Georgia, USA
- Kimberley Treinen, Ph.D.
  Sunovion Pharmaceuticals, Inc.
  Marlborough, Massachusetts, USA