# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.T.D. Watson, Ph.D., Study Scientist
  S.S. Auerbach, Ph.D.
  C.R. Blystone, Ph.D.
  B.J. Collins, M.S.P.H.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  J.M. Fostel, Ph.D.
  P.M. Foster, Ph.D. (Retired)
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D. (Retired)
  S.A. Masten, Ph.D.
  B.S. McIntyre, Ph.D.
  K.R. Ryan, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  V.L. Sutherland, Ph.D.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
- Southern Research, Birmingham, Alabama, USA
  Conducted studies and evaluated fetal findings
  C.D. Hébert, Ph.D., Principal Investigator
  E. Mylchreest, Ph.D., Study Director
  K.K. Daniels, Ph.D.
  A. Penman, Ph.D.
  A.H. Stokes, Ph.D.
- Social & Scientific Systems, Inc., Research Triangle Park, North Carolina, USA
  Provided statistical analyses
  M.V. Smith, Ph.D., Principal Investigator
  L.J. Betz, M.S.
  S.F. Harris, M.S.
  J.D. Krause, Ph.D.
  C.G. Leach, M.S.