# References

1 Lide DR, Milne GWA. Handbook of data on organic compounds, 3rd ed., Vol. 1, No. 2228. Boca Raton, FL: CRC Press. 1994.
2 U.S. Environmental Protection Agency (USEPA). Estimation Programs Interface Suite™ for Microsoft Windows©, Ver. 4.1. Washington, DC: U.S. Environmental Protection Agency; 2014. https://www.epa.gov/tsca-screening-tools/estimation-program-interface-epi-suite-tm-program-modifications-new-features
3 Eastman Chemical Company. Safety Data Sheet: Crude MCHM. Version 3.0. Kingsport (TN): Eastman Chemical Company; 2015.
4 Foreman WT Rose DL Chambers DB Crain AS Murtagh LK Thakellapalli H Wang KK Determination of (4-methylcyclohexyl) methanol isomers by heated purge-and-trap GC/MS in water samples from the 2014 Elk River, West Virginia, chemical spill. Chemosphere. 2015;131:217–224. 10.1016/j.chemosphere.2014.11.006 25542639
5 Gallagher DL Phetxumphou K Smiley E Dietrich AM Tale of two isomers: complexities of human odor perception for cis-and trans-4-methylcyclohexane methanol from the chemical spill in West Virginia. Environ Sci Technol. 2015;49(3):1319–1327. 10.1021/es5049418 25541902
6 West Virginia Office of the Governor. After action review: Emergency response to January 9, 2014, Freedom Industries chemical leak. Charleston, WV: State of West Virginia Office of the Governor; Homeland Security and Emergency Management; and West Virginia National Guard; 2015. http://www.governor.wv.gov/Documents/After%20Action%20Review.PDF [Accessed: September 21, 2016]
7 West Virginia Poison Center (WVPC). Factsheet: Freedom Industries, Elk River chemical spill, February 10, 2014. Washington, DC: West Virginia Poison Center; and Georgetown University, Mid-Atlantic Center for Children’s Health and the Environment; 2014. http://www.legis.state.wv.us/legisdocs/2014/committee/interim/water/Documents/Bureau%20for%20Public%20Health%20Packet.pdf [Accessed: September 21, 2016]
8 Centers for Disease Control and Prevention (CDC). Summary report of short-term screening level calculation and analysis of available animal studies for MCHM. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; 2014. https://emergency.cdc.gov/chemical/MCHM/westvirginia2014/mchm.asp
9 Whelton AJ McMillan L Connell M Kelley KM Gill JP White KD Gupta R Dey R Novy C Residential tap water contamination following the Freedom Industries chemical spill: Perceptions, water quality, and health impacts. Environ Sci Technol. 2015;49(2):813–823. 10.1021/es5040969 25513829
10 Toxicology Excellence for Risk Assessment (TERA). Report of expert panel review of screening levels for exposure to chemicals from the January 2014 Elk River spill. Charleston (WV): West Virginia Division of Homeland Security and Emergency Management, West Virginia Testing Assessment Project; 2014.
11 Eastman Kodak Company. Four-week oral toxicity study of 4-methylcyclohexane methanol in the rat. Rochester, NY: Eastman Kodak Company, Health and Environment Laboratories, Toxicological Sciences Laboratory; 1990. TX-89-296; HAEL No. 89-0081; Accession. No. 907670. https://www.eastman.com/Literature_Center/Misc/Pure_Distilled_MCHM-28-Day_Oral_Feeding_Study.pdf
12 National Toxicology Program (NTP). West Virginia chemical spill: Nematode (caenorhabditis elegans) toxicity study. March 2015 update. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2015. https://ntp.niehs.nih.gov/ntp/research/areas/wvspill/celegans_wvupdate_march2015_508.pdf
13 National Toxicology Program (NTP). West Virginia chemical spill: Zebrafish developmental toxicity study. June 2015 update. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2015. https://ntp.niehs.nih.gov/ntp/research/areas/wvspill/zebrafish_update_june2015_508.pdf
14 National Toxicology Program (NTP). West Virginia chemical spill: Zebrafish photomotor response study. August 2015 update. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2015. https://ntp.niehs.nih.gov/ntp/research/areas/wvspill/zebrafish_update_aug2015_508.pdf
15 Eastman Kodak Company. Acute toxicity of 4-methylcyclohexane methanol. Rochester, NY: Eastman Kodak Company, Health and Environment Laboratories, Toxicological Sciences Laboratory; 1990. TX-90-5; HAEL No. 89 0081; Accession No. 907670. https://www.eastman.com/Literature_Center/Misc/Pure_Distilled_MCHM-Acute_Toxicity_Battery_Containing_5_Study_Reports.pdf
16 National Toxicology Program (NTP). West Virginia chemical spill: Mouse dermal irritation and hypersensitivity study. June 2015 update. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2015. https://ntp.niehs.nih.gov/ntp/research/areas/wvspill/mouse_dermal_wvupdate_508.pdf
17 National Toxicology Program (NTP). NTP technical report on the dermal hypersensitivity and irritancy studies of 4-methylcyclohexanemethanol (CAS No. 34885-03-5) and crude 4-methylcyclohexanemethanol administered topically to female BALB/c mice. Research Triangle Park (NC): U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; In Preparation. 2019.
18 National Toxicology Program (NTP). West Virginia chemical spill: 5-day rat toxicogenomic studies. July 2016 update. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2016. https://ntp.niehs.nih.gov/ntp/research/areas/wvspill/tgmx_update_july2016_508.pdf
19 Schade CP Wright N Gupta R Latif DA Jha A Robinson J Self-reported household impacts of large-scale chemical contamination of the public water supply, Charleston, West Virginia, USA. PLoS One. 2015;10(5):e0126744. 10.1371/journal.pone.0126744 25951197
20 National Toxicology Program (NTP). West Virginia chemical spill: 5-day toxicogenomic studies: In vivo micronucleus assay component. February 2015 update. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2015. https://ntp.niehs.nih.gov/ntp/research/areas/wvspill/micronucleus_wvfeb2015_508.pdf
21 National Toxicology Program (NTP). West Virginia chemical spill: Bacterial mutagenicity study. July 2015 update. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2015. https://ntp.niehs.nih.gov/ntp/research/areas/wvspill/bacterial_mutagenesis_july2015_508.pdf
22 Chernoff N Setzer RW Miller DB Rosen MB Rogers JM Effects of chemically induced maternal toxicity on prenatal development in the rat. Teratology. 1990;42(6):651–658. 10.1002/tera.1420420610 2087686
23 U.S. Environmental Protection Agency (USEPA). Guidelines for developmental toxicity risk assessment. Washington, DC: U.S. Environmental Protection Agency, Risk Assessment Forum; 1991. EPA Document No. EPA/600/FR-91/001.
24 Tyl RW Commentary on the role of maternal toxicity on developmental toxicity. Birth Defects Res B Dev Reprod Toxicol. 2012;95(3):262–266. 10.1002/bdrb.21015 22706915
25 Organisation for Economic Co-operation and Development (OECD). OECD guideline for the testing of chemicals, test no. 44, prenatal developmental toxicity study. Paris, France: Organisation for Economic Co-operation and Development; 2001.
26 Makris SL Solomon HM Clark R Shiota K Barbellion S Buschmann J Ema M Fujiwara M Grote K Hazelden KP Terminology of developmental abnormalities in common laboratory mammals (version 2). Congenit Anom (Kyoto). 2009;49(3):123–246. 10.1111/j.1741-4520.2009.00239.x 20002907
27 Suckow MA Weisbroth SH Franklin CL The laboratory rat. 2nd ed. Amsterdam, Netherlands: Elsevier; 2006.
28 Hayes AW Kruger CL Hayes’ principles and methods of toxicology. 6th ed. Boca Raton (FL): CRC Press; 2014. p. 1670–1672. 10.1201/b17359
29 Salewski E Färbemethode zum makroskopischen nachweis von implantationsstellen am uterus der ratte. Naunyn Schmiedebergs Arch Pharmacol. 1964;247(4):367.10.1007/BF02308461
30 Tyl RW Marr MC Developmental toxicity texting – methodology. Developmental and Reporductive Toxicology. 2nd ed. New York (NY): Taylor and Francis Group; 2006. p. 201–261.
31 Staples RE Detection of visceral alterations in mammalian fetuses. Teratology. 1974;9:A37–A38.
32 Stuckhardt JL Poppe SM Fresh visceral examination of rat and rabbit fetuses used in teratogenicity testing. Teratog Carcinog Mutagen. 1984;4(2):181–188. 10.1002/tcm.1770040203 6145223
33 Thompson RF Basic neuroanatomy. Foundations of Physiological Psychology. New York (NY): Harper and Row Publishers; 1967. p. 79–82.
34 Marr MC Price CJ Myers CB Morrissey RE Developmental stages of the CD®(Sprague‐Dawley) rat skeleton after maternal exposure to ethylene glycol. Teratology. 1992;46(2):169–181. 10.1002/tera.1420460210 1440420
35 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121.10.1080/01621459.1955.10501294
36 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27:103–117. 10.2307/2528930 5547548
37 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28:519–531. 10.2307/2556164 5037867
38 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33:386–389. 10.2307/2529789 884197
39 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42:183–186. 10.2307/2531254 3719054
40 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252.10.1080/00401706.1964.10490181
41 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1/2):133–145. 10.2307/2333011
42 Dixon WJ Massey FJ Jr Introduction to statistical analysis. 2nd ed. New York (NY): McGraw-Hill Book Company, Inc; 1957. p. 276–278, 412. 10.2307/2332898
43 Hsu JC The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992;1(2):151–168.
44 Armitage P Tests for linear trends in proportions and frequencies. Biometrics. 1955;11(3):375–386. 10.2307/3001775
45 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
46 Zorrilla EP. Multiparous species present problems (and possibilities) to developmentalists. Dev Psychobiol. 1997; 30(2):141-150. 10.1002/(SICI)1098-2302(199703)30:2<141::AID-DEV5>3.0.CO;2-Q
47 Pendergast JF Gagne SJ Lindstrom MJ Encyclopedia of Biostatistics. London, UK: John Wiley and Sons; 2005. Correlated binary data. 10.1002/0470011815.b2a10018
48 Li B Lingsma HF Steyerberg EW Lesaffre E Logistic random effects regression models: A comparison of statistical packages for binary and ordinal outcomes. BMC Med Res Methodol. 2011;11(1):77. 10.1186/1471-2288-11-77 21605357
49 Code of Federal Regulations (CFR). 21:Part 58.
50 National Toxicology Program (NTP). DART-02: Growth and clinical finding tables (I), pathology tables (PA), developmental and reproductive tables (R) from NTP developmental and reproductive toxicity studies. Research Triangle Park, NC. 2019. 10.22427/NTP-DATA-DART-02
51 Pickering RG Pickering CE Studies of rat alkaline phosphatase. II. Some applications of the methods for detecting the isoenzymes of plasma alkaline phosphatase in rats. Arch Toxicol. 1978;39(4):267–287. 10.1007/BF00296387 580371
52 Waner T Nyska A The influence of fasting on blood glucose, triglycerides, cholesterol, and alkaline phosphatase in rats. Vet Clin Pathol. 1994;23(3):78–80. 10.1111/j.1939-165X.1994.tb00683.x 12666020
53 Eastman Chemical Company. Safety Data Sheet: Crude MCHM. Version 3.1. Kingsport (TN): Eastman Chemical Company; 2016.
54 Chernoff N Rogers EH Gage MI Francis BM The relationship of maternal and fetal toxicity in developmental toxicology bioassays with notes on the biological significance of the “no observed adverse effect level”. Reprod Toxicol. 2008;25(2):192–202. 10.1016/j.reprotox.2007.12.001 18242052
55 Nitzsche D. Effect of maternal feed restriction on prenatal development in rats and rabbits–A review of published data. Regul Toxicol Pharm. 2017; 90:95-103. 10.1016/j.yrtph.2017.08.009
56 Rogers JM Francis BM Barbee BD Chernoff N Developmental toxicity of bromoxynil in mice and rats. Fundam Appl Toxicol. 1991;17(3):442–447. 10.1016/0272-0590(91)90195-A 1794648
57 Tsutomu N Shigeru M Tetsuo Y Mitsuru S Tomoko N Minoru S Akio Y Teratogenicity study of tri-n-butyltin acetate in rats by oral administration. Toxicol Lett. 1991;55(1):109–115. 10.1016/0378-4274(91)90032-2 1998192
58 Fujinaga M Baden JM Mazze RI Susceptible period of nitrous oxide teratogenicity in Sprague‐Dawley rats. Teratology. 1989;40(5):439–444. 10.1002/tera.1420400505 2623632
59 Foulon O Girard H Pallen C Urtizberea M Repetto–Larsay M Blacker AM Induction of supernumerary ribs with sodium salicylate. Reprod Toxicol. 1999;13(5):369–374. 10.1016/S0890-6238(99)00029-5 10560585
60 Kawanishi CY Hartig P Bobseine KL Schmid J Cardon M Massenburg G Chernoff N Axial skeletal and Hox expression domain alterations induced by retinoic acid, valproic acid, and bromoxynil during murine development. J Biochem Mol Toxicol. 2003;17(6):346–356. 10.1002/jbt.10098 14708090
61 Branch S, Rogers JM, Brownie CF, Chernoff N. Supernumerary lumbar rib: Manifestation of basic alteration in embryonic development of ribs. J Appl Toxicol. 1996; 16(2):115-119. 10.1002/(SICI)1099-1263(199603)16:2<115::AID-JAT309>3.0.CO;2-H
62 Connelly LE, Rogers JM. Methanol causes posteriorization of cervical vertebrae in mice. Teratology. 1997; 55(2):138-144. 10.1002/(SICI)1096-9926(199702)55:2<138::AID-TERA4>3.0.CO;2-%23
63 Wéry N, Narotsky MG, Pacico N, Kavlock RJ, Picard JJ, Gofflot F. Defects in cervical vertebrae in boric acid‐exposed rat embryos are associated with anterior shifts of hox gene expression domains. Birth Defects Res Part A: Clin Mol Teratol. 2003; 67(1):59-67. 10.1002/bdra.10031
64 Beyer PE Chernoff N The induction of supernumerary ribs in rodents: role of the maternal stress. Teratog Carcinog Mutagen. 1986;6(5):419–429. 10.1002/tcm.1770060508 2878507
65 Foulon O, Jaussely C, Repetto M, Urtizberea M, Blacker AM. Postnatal evolution of supernumerary ribs in rats after a single administration of sodium salicylate. J Appl Toxicol. 2000; 20(3):205-209. 10.1002/(SICI)1099-1263(200005/06)20:3<205::AID-JAT635>3.0.CO;2-G
66 Chernoff N Rogers JM Turner CI Francis BM Significance of supernumerary ribs in rodent developmental toxicity studies: postnatal persistence in rats and mice. Toxicol Sci. 1991;17(3):448–453. 10.1016/0272-0590(91)90196-B 1794649
67 Beck SL Assessment of adult skeletons to detect prenatal exposure to trypan blue in mice. Teratology. 1983;28(2):271–285. 10.1002/tera.1420280217 6648830
68 Khera KS Common fetal aberrations and their teratologic significance: A review. Toxicol Sci. 1981;1(1):13–18. 10.1093/toxsci/1.1.13 6135638
69 Daston GP Seed J Skeletal malformations and variations in developmental toxicity studies: interpretation issues for human risk assessment. Birth Defects Res B Dev Reprod Toxicol. 2007;80(6):421–424. 10.1002/bdrb.20135 18157902
70 Benson SM Ruestow P Keeton KA Novick RM Marsh GM Paustenbach DJ The 2014 crude 4-methylcyclohexanemethanol chemical release and birth outcomes in West Virginia. Arch Environ Occup Health. 2018;73(5):292–301. 10.1080/19338244.2017.1350132 28692341
71 Sanders S Analysis of birthweight after the January 9, 2014 chemical spill in Charleston, West Virginia. Charleston (WV): West Virginia Department of Health and Human Resources, Office of Maternal, Child and Family Health; 2016. https://www.wvdhhr.org/mcfh/files/birthweightanalysis.pdf.
72 Advanced Chemistry Development (ACD). SciFinder^®^ Spectrum ID 34885035-HNMR. Predicted NMR data calculated using Advanced Chemistry Development, Inc., Software V11.01. Toronto, Ontario, Canada: ACD Labs; 1994.
73 National Institute of Standards and Technology (NIST). Mass Spectral Library, Version d.OF; trans, ID 18215, cis, ID 18228. Gaithersburg (MD): National Institute of Standards and Technology; 2008.
74 American Chemical Society (ACS). SciFinder® Spectrum ID BR08924. 2014.
75 American Chemical Society (ACS). SciFinder® Spectrum ID NC_05067. 2014.
76 Allen CFH Ball WL Young DM Dihydro-p-tolualdehyde. Can J Res. 1933;9(2):169–174. 10.1139/cjr33-078