# Conclusions

Under the conditions of this prenatal study, there was clear evidence of developmental toxicity of MCHM in Hsd:Sprague Dawley^®^ SD^®^ rats based on reduced fetal weight, adrenal malformations, and increased malformations of the axial skeleton (short cervical SNRs, full thoracolumbar SNRs, and costal cartilage not fused to the sternum). These findings occurred in fetuses of dams administered 400 mg/kg and in the absence of overt maternal toxicity.