# Discussion

4-Methylcyclohexanemethanol (MCHM) is sold as a crude mixture (containing 68–89% MCHM) and is used to remove impurities during the processing of coal.^53^ On January 9, 2014, an estimated 10,000 gallons of a mixture containing 75% MCHM leaked into the Elk River upstream of the intake for the West Virginia American Water Company’s Elk River plant.^6^ In response, the Centers for Disease Control and Prevention (CDC) and the Agency for Toxic Substances and Disease Registry recommended a 1 ppm drinking water health advisory level that was based on the available toxicity data and nominated MCHM and other chemicals present in the Elk River spill for toxicological evaluation by NTP. Because of the potential for exposure of pregnant women to MCHM and the absence of developmental toxicity data, NTP conducted toxicity studies in Hsd:Sprague Dawley^®^ SD^®^ rats to evaluate the potential effects of MCHM on pregnant rats and fetal development. The guideline prenatal developmental toxicity studies discussed in this report provide important animal data that can be used to address the adequacy of the 1 ppm advisory level in protecting sensitive human populations.

MCHM dose levels selected for the range-finding study were 0, 150, 300, 600, and 900 mg/kg body weight per day (mg/kg/day). All dams in the 900 mg/kg group and three dams in the 600 mg/kg group displayed clinical signs of overt toxicity and were euthanized moribund and/or removed from the study by gestational day (GD) 10. The remaining 600 mg/kg dams experienced reduced body weight gain during gestation and reduced gravid uterine weight compared to vehicle control dams. Increased postimplantation loss was also observed at this dose, and although not statistically significant, this finding indicates test article-related toxicity to dams and/or pups. No signs of maternal toxicity were present at 300 mg/kg; however, exposure to MCHM resulted in lower fetal body weights in the 300 and 600 mg/kg groups. Therefore, because maternal toxicity occurred at or above 600 mg/kg in the dose range-finding study, 400 mg/kg was selected as the high dose for the prenatal developmental toxicity study.

In the prenatal developmental toxicity study, no signs of overt toxicity were evident in dams following daily gavage of 0, 50, 100, 200, or 400 mg/kg. Total protein concentrations were decreased in dams administered 100 mg/kg or greater, which was driven by a decrease in globulin concentrations in the same dams. Several serum proteins comprise the globulin fraction and include proteins produced by both B-lymphocytes (immunoglobulins) and hepatocytes (e.g., haptoglobulin, complement, C-reactive protein); however, the mechanism of the decreased globulins in this study is not known and the toxicological significance of these changes is unclear. Increased triglycerides (400 mg/kg) and decreased glucose levels (200 and 400 mg/kg) were also observed. It is possible that differences in feed consumption might be responsible for these changes; however, toxicogenomic data from MCHM-treated adult male Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats could provide additional context. In addition to the minor alterations in triglyceride and glucose levels, exposure to MCHM altered the expression of several genes in the liver involved in pathways known to modulate fatty acid metabolism and cholesterol homeostasis.^20^ These findings suggest that MCHM might affect lipid and/or carbohydrate metabolism; however, the mechanism underlying these changes is not known.

Exposure to MCHM significantly affected embryo-fetal development. Fetal body weight was decreased in an exposure-dependent manner in both the dose range-finding and prenatal developmental toxicity studies with lower fetal body weight observed at levels greater than or equal to 300 mg/kg. Reduced fetal body weight is a common toxicological response following in utero exposure and is responsible for lowest-observable-adverse-effect levels (LOAELs) in 75% of NTP prenatal developmental toxicity studies conducted in rats.^54^ Fetal body weight reductions might also be associated with lower maternal body weight and body weight gain. Such a finding could be secondary to maternal stress and/or toxicity as maternal feed restriction studies in the rat and rabbit demonstrate a relationship between reduced maternal weight gain and lower fetal body weights.^55^ The present study, however, demonstrated that the MCHM-related reduction in fetal body weight occurred at exposure levels where the adjusted maternal body weight remained unaffected in the 300 and 400 mg/kg dams.

Examination of visceral organs revealed exposure-related increases in kidney variations as well as adrenal variations and malformations, with glands appearing grossly necrotic (histopathology was not performed in this study). One 50 mg/kg fetus and a total of three fetuses from three litters in the 400 mg/kg group had misshapen and discolored adrenals and discolored kidneys. In addition, one 400 mg/kg fetus also had findings of a misshapen (malformation) and discolored left ovary. Although the etiology of these findings is uncertain, MCHM-related effects on the kidney were previously observed in a 28-day gavage study in adult Sprague Dawley rats. Both males and females displayed proximal tubular degeneration at 400 mg/kg/day and males displayed slight increases in relative kidney weights at 25, 100, and 400 mg/kg/day.^11^ Despite the low incidences of adrenal and kidney findings, these occurred at rates greater than those observed in the historical controls for the Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rat used by NTP in prenatal developmental toxicity studies.

MCHM-related teratogenicity was also evidenced by increased incidences of skeletal malformations. These included exposure-related increases in the incidences of cartilage not fused to the sternum and full thoracolumbar supernumerary ribs (SNRs); the latter demonstrating a statistically significant increase in fetuses exposed to 400 mg/kg. Full thoracolumbar SNRs were observed in 10% and 33% of fetuses and litters, respectively, in the 400 mg/kg group. Both measures were significantly higher than those in concurrent vehicle controls and exceeded the historical control incidence in fetuses (0.3–3.5%) and litters (5–32%) observed in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats used in prenatal developmental toxicity studies conducted by NTP.

Despite varying levels of background incidence, an increase in thoracolumbar SNRs is a common finding following in utero exposure to a range of test articles in the rat and mouse model. Notable examples include methanol,^56^ tri-n-butyltin acetate,^57^ nitrous oxide,^58^ sodium salicylate,^59^ retinoic acid, valproic acid, and bromoxynil.^56,60^ An increased incidence of SNRs has been attributed to alterations of the underlying mechanisms responsible for anteriorization/posteriorization patterning of the axial skeleton.^60-63^ Alternatively, an increase in SNRs has been attributed to maternal stress; however, this effect may be species-dependent as maternal restraint induced an elevated incidence of SNRs in mice but not in rats.^64^ Given the absence of overt maternal stress or toxicity in dams administered 400 mg/kg MCHM, the observed increase in SNRs at this dose is likely due to MCHM treatment; however, the underlying mechanism(s) responsible for the increase in SNRs cannot be ascertained under the conditions of this study. The exposure-related increase in full thoracolumbar SNRs in this study is biologically significant. Full thoracolumbar SNRs have been shown to persist through postnatal development following sodium salicylate exposure to Sprague Dawley dams on GD 9 and longitudinal assessment of pups from postnatal day (PND) 1 to PND 54.^65^ A similar finding was observed in bromoxynil-^66^ and acetazolamide-induced SNRs in mice.^67^ Therefore, the exposure-related increase of full thoracolumbar SNRs in the present study might represent a permanent structural change that is unlikely to be remodeled and resolved with continued growth.

MCHM also resulted in exposure-related increases in other skeletal anomalies including misaligned costal cartilage and unossified or incomplete ossification of the sternebrae and thoracic centra. Although these variations might not represent adverse functional deficits per se, it is important to note their incidence in conjunction with other endpoints associated with developmental delay. The overall delays in ossification and reduction in fetal body weight suggest that MCHM exposure results in an overall growth retardation. Several studies demonstrate a similar relationship between fetal body weight and ossification delays^68,69^; however, some delays in ossification resolve during subsequent postnatal development as shown in rats exposed to ethylene glycol in utero.^34^

Taken together, the data from the range-finding and prenatal developmental toxicity studies demonstrate the potential for MCHM to adversely affect fetal development in the Sprague Dawley rat. A maternal NOEL of 50 mg/kg was identified based on changes in clinical chemistry observed at doses ≥100 mg/kg, as well as reduced weight gain at 400 mg/kg and overt toxicity observed at 600 and 900 mg/kg in the dose range-finding study. The minimal alterations in clinical chemistry would not be expected to affect fetal development. A fetal NOEL of 200 mg/kg was based on findings of reduced fetal body weight and increased incidence of skeletal malformations at 400 mg/kg.

These data provide important context to address the recommended 1 ppm health advisory level for drinking water set by the CDC. Consumption of drinking water containing 1 ppm MCHM represents an equivalent exposure of 0.03 mg/kg in adults (70 kg adult consuming 2 L per day), 0.04 mg/kg/day in pregnant women (58 kg female consuming 2.5 L per day), and 0.1 mg/kg/day in children (10 kg child consuming 1 L per day). Thus, a significant margin of exposure (>1000-fold) exists between the fetal NOEL of 200 mg/kg identified in the present study and the estimated human exposure at the 1 ppm screening level for MCHM. In addition, a review of hospital records from Charleston, West Virginia, and the surrounding area, did not find an association between adverse birth outcomes and exposure to MCHM or other chemicals present in the spill.^70,71^