# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-DART-02.^50^

## Dose Range-finding Study in Rats

### Maternal Findings

#### Viability and Clinical Observations

Dose-related mortality and clinical observations of toxicity occurred in dams in the 600 and 900 mg/kg groups (Table 2; Appendix D^50^). The 900 mg/kg group was euthanized by gestation day (GD) 8 due to overt toxicity. Clinical observations in these animals included ataxia, cold to touch, clear ocular discharge, excessive salivation, lethargy/hypoactivity, and/or piloerection. Additionally, three animals in the 600 mg/kg group were euthanized on GD 9 to 10 with clinical observations similar to those that were observed in the 900 mg/kg group. No clinical observations of toxicity occurred in dams administered 300 mg/kg or less.

Table 2 Maternal Disposition of Rats in the Dose Range-finding Gavage Study of 4-Methylcyclohexanemethanol

| 0 mg/kg | 150 mg/kg | 300 mg/kg | 600 mg/kg | 900 mg/kg
Time-mated Females | 10 | 10 | 10 | 10 | 10
Pregnant (on GD 21) | 9 | 9 | 8 | 7 | 0
Euthanized Moribund – Pregnant | 0 | 0 | 0 | 3^a^ | 2^b^
Group Removal | 0 | 0 | 0 | 0 | 8^c^
Delivered Early | 0 | 1 | 1 | 0 | 0
Nonpregnant (on GD 21) | 1 | 0 | 1 | 0 | 0

GD = gestation day.

^a^ Dams were euthanized on GD 9 and GD 10.

^b^ Dams were euthanized on GD 8.

^c^ Remaining dams from the 900 mg/kg group were removed on GD 7 or 8.

#### Body Weights and Feed Consumption

Average body weights of the 600 and 900 mg/kg groups were 9% and 14% lower than those of the vehicle controls on GD 8, respectively (Appendix D^50^). Maternal body weight gain (GD 6 to 21) was 44% lower than that in the vehicle controls in dams administered 600 mg/kg that were necropsied on GD 21 (Figure 3 and Table 3). This lower weight gain was associated with the body weight loss that occurred on GD 6 to 9 and toward the end of gestation (Table 3; Appendix D^50^). Body weights and body weight gains of the 150 and 300 mg/kg groups were similar to those of the vehicle control groups throughout gestation. When adjusted for gravid uterine weight (at necropsy), maternal body weight was 4% and 2% higher in 150 and 300 mg/kg groups, respectively, and 5% lower in the 600 mg/kg group than that of the vehicle controls (Table 5).

Figure 3

Maternal Growth Curves for Pregnant Rats Administered 4-Methylcyclohexanemethanol by Gavage in the Dose Range-finding Study

Information for statistical significance in maternal weights is provided in Table 3 and Appendix D.^50^

Table 3 Summary of Maternal Body Weight Gains of Rats in the Dose Range-finding Gavage Study of 4-Methylcyclohexanemethanol^a^

Gestation Day Interval | 0 mg/kg | 150 mg/kg | 300 mg/kg | 600 mg/kg | 900 mg/kg
6–21 | 112.1 ± 9.4 (9) | 132.2 ± 7.8 (9) | 129.6 ± 5.0 (9) | 63.1 ± 16.8** (7) | –
3–6 | 11.8 ± 0.7 (9) | 13.7 ± 1.8 (10) | 12.9 ± 1.5 (9) | 10.7 ± 1.1 (10) | 14.9 ± 1.4 (9)
6–9 | 10.5 ± 0.8** (9) | 9.2 ± 1.2 (10) | 8.6 ± 1.4 (9) | −14.9 ± 5.2** (10) | –
9–12 | 16.9 ± 0.9 (9) | 18.0 ± 1.0 (10) | 19.1 ± 1.1 (9) | 18.0 ± 2.4 (7) | –
12–15 | 15.2 ± 2.1 (9) | 17.4 ± 1.8 (10) | 18.3 ± 0.7 (9) | 16.2 ± 3.1 (7) | –
15–18 | 35.0 ± 3.7 (9) | 40.5 ± 2.4 (10) | 38.6 ± 2.3 (9) | 16.4 ± 5.1** (7) | –
18–21 | 34.5 ± 3.8 (9) | 49.1 ± 2.9 (9) | 45.1 ± 2.4 (9) | 18.4 ± 8.0* (7) | –

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Williams or Dunnett test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Body weight gains for pregnant animals are given in grams. Data are displayed as mean ± standard error. Number of dams weighed is given in parentheses.

Mean feed consumption from GD 6 to 21 was 13% less than that of the vehicle control groups in dams administered 600 mg/kg. This overall reduction was due to a 52% lower feed consumption during GD 6 to 9, which was associated with lower body weights and negative weight gains during that interval (Table 3 and Table 4). Feed consumption in the 150 and 300 mg/kg groups was similar to or greater than that of the vehicle controls throughout gestation.

Table 4 Summary of Maternal Feed Consumption of Rats in the Dose Range-finding Gavage Study of 4-Methylcyclohexanemethanol^a^

Gestation Day Interval | 0 mg/kg | 150 mg/kg | 300 mg/kg | 600 mg/kg | 900 mg/kg
6–21 | 19.5 ± 0.33 (9) | 20.8 ± 0.56 (9) | 21.8 ± 0.51* (9) | 17.0 ± 1.07 (7) | –
3–6 | 17.8 ± 0.27 (9) | 18.6 ± 0.58 (10) | 18.6 ± 0.48 (9) | 17.0 ± 0.38 (10) | 17.8 ± 0.40 (9)
6–9 | 17.7 ± 0.37** (9) | 17.7 ± 0.47 (10) | 17.4 ± 0.57 (9) | 8.4 ± 1.67** (10) | –
9–12 | 18.8 ± 0.32 (9) | 19.7 ± 0.44 (10) | 21.3 ± 0.66* (9) | 16.2 ± 0.97 (7) | –
12–15 | 18.6 ± 0.45* (9) | 19.5 ± 0.44 (9) | 22.0 ± 0.63** (9) | 18.7 ± 1.37 (7) | –
15–18 | 21.5 ± 0.68 (9) | 23.3 ± 0.76 (10) | 24.3 ± 0.65* (9) | 20.2 ± 1.28 (7) | –
18–21 | 20.9 ± 0.63 (9) | 23.4 ± 0.70 (9) | 24.1 ± 0.84* (9) | 19.1 ± 1.33 (7) | –

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Shirley or Dunn test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Feed consumption for pregnant females is given in grams/day. Data are displayed as mean ± standard error. Number of dams with feed consumption measured is given in parentheses.

#### Maternal and Litter Observations

Gross observations in the 600 mg/kg group at necropsy consisted of stomachs distended with food and were considered dose related (this occurred in three moribund euthanasia animals and in two animals at scheduled euthanasia on GD 21) (Appendix D^50^). One moribund 600 mg/kg animal was observed to have a dilated bladder; it is not clear if this was related to chemical administration. Increased relative kidney and liver weights in the 600 mg/kg group were considered to be secondary to the decreased body weights of dams in this group (Appendix D^50^).

The number of pregnant females and the mean numbers of corpora lutea and implantation sites were similar across the dose groups (Table 5). One 150 mg/kg dam delivered on GD 20, and one 300 mg/kg dam delivered in the morning of GD 21 shortly before scheduled necropsy; these early deliveries were considered incidental and not related to chemical exposure (Table 2 and Table 5).

Table 5 Summary of Uterine Content Data for Rats in the Dose Range-finding Gavage Study of 4-Methylcyclohexanemethanol

| 0 mg/kg | 150 mg/kg | 300 mg/kg | 600 mg/kg | 900 mg/kg
Pregnancy Summary
Mated females | 10 | 10 | 10 | 10 | 10
Pregnant females | 9 | 10 | 9 | 10 | 9
Pregnant females examined on GD 21^a^ | 9* | 9 | 8 | 7 | 0
Corpora lutea per female^b^ | 16.67 ± 1.24 (9) | 16.20 ± 0.47 (10) | 16.22 ± 0.94 (9)^c^ | 15.71 ± 0.75 (7)
Implantations per female^b^ | 11.67 ± 1.67 (9) | 13.56 ± 0.94 (9) | 14.50 ± 0.82 (8) | 15.00 ± 0.79 (7)
Percent postimplantation loss^b^ | 9.81 ± 2.71 (9) | 5.68 ± 3.36 (9) | 2.08 ± 1.40 (8) | 53.34 ± 17.46 (7)
Total resorptions per litter^b^ | 1.22 ± 0.40 (9) | 0.56 ± 0.29 (9) | 0.25 ± 0.16 (8) | 8.00 ± 2.86 (7)
Early resorptions per litter^b^ | 1.11 ± 0.42 (9) | 0.56 ± 0.29 (9) | 0.13 ± 0.13 (8) | 7.57 ± 2.92 (7)
Late resorptions per litter^b^ | 0.11 ± 0.11 (9) | 0.00 ± 0.00 (9) | 0.13 ± 0.13 (8) | 0.43 ± 0.30 (7)
Dead fetuses per litter^b^ | 0.00 ± 0.00 (9) | 0.00 ± 0.00 (9) | 0.00 ± 0.00 (8) | 0.29 ± 0.29 (7)
Number of early resorptions | 10 | 5 | 1 | 53
Number of late resorptions | 1 | 0 | 1 | 3
Number of dead fetuses | 0 | 0 | 0 | 2
Number of whole litter resorptions^a^ | 0* | 0 | 0 | 2
Live Fetuses^b^
Number of live fetuses | 94 | 117 | 114 | 47
Live fetuses per litter | 10.44 ± 1.54 (9) | 13.00 ± 1.17 (9) | 14.25 ± 0.92 (8) | 6.71 ± 2.52 (7)
Live male fetuses per litter | 4.56 ± 1.25 (9) | 5.44 ± 0.84 (9) | 6.63 ± 0.56 (8) | 2.71 ± 1.19 (7)
Live female fetuses per litter | 5.89 ± 1.09 (9) | 7.56 ± 1.02 (9) | 7.63 ± 0.84 (8) | 4.00 ± 1.51 (7)
Percent live male fetuses per litter | 37.25 ± 8.84 (9) | 42.87 ± 5.60 (9) | 47.25 ± 3.98 (8) | 34.72 ± 10.21 (5)
Fetal Weight (g)^d^
Fetal weight per litter | 5.34 ± 0.16 (9)** | 5.11 ± 0.11 (9) | 4.72 ± 0.07 (8)* | 3.28 ± 0.37 (5)**
Male weight per litter | 5.38 ± 0.17 (8)** | 5.26 ± 0.11 (9) | 4.79 ± 0.08 (8)** | 3.71 ± 0.30 (4)**
Female weight per litter | 5.25 ± 0.17 (9)** | 4.98 ± 0.09 (9) | 4.64 ± 0.08 (8)* | 3.23 ± 0.37 (5)**
Gravid Uterine Weight (g)^e^
Gravid uterine weight | 75.88 ± 10.09 (9) | 88.80 ± 7.15 (9) | 92.78 ± 4.70 (8) | 40.59 ± 14.31 (7)*
Terminal body weight | 349.9 ± 11.9 (9) | 373.9 ± 11.5 (9) | 370.5 ± 8.1 (9) | 300.0 ± 16.1 (7)*
Adjusted body weight | 274.06 ± 2.81 (9) | 285.06 ± 5.93 (9) | 280.16 ± 6.02 (8) | 259.40 ± 5.77 (7)

Values are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to end of study.

* Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column).

** p ≤ 0.01.

GD = gestation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

^b^ Statistical analysis on number per litter performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One dam in the 300 mg/kg group delivered early on GD 21, shortly before scheduled necropsy, and was examined for corpora lutea.

^d^ Statistical analysis performed using a mixed-effects linear model with litter as a random effect (trend and pairwise).

^e^ Statistical analysis performed by the Jonckheere (trend) and William or Dunnett (pairwise) tests; adjusted body weight = terminal body weight minus gravid uterine weight.

There was an exposure-related effect on percent postimplantation loss as a result of an increase in the number of early and late resorptions and dead fetuses noted in the 600 mg/kg group (Table 5). The numbers of live and dead fetuses and early and late resorptions in the 150 and 300 mg/kg groups were similar to those in the vehicle controls. The fetal sex ratios were similar across the dose groups.

There was an exposure-related effect on fetal weights at doses of 300 and 600 mg/kg (Table 5). Compared to the vehicle controls, mean fetal weights per litter were decreased 12% and 39% in the 300 and 600 mg/kg groups, respectively, and the magnitudes of these effects were similar in male and female fetuses. In the 150 mg/kg group, mean fetal weight per litter was marginally less (4%) than that in the vehicle controls.

### Fetal Findings

#### External

No external morphological abnormalities were attributed to MCHM administration at 150, 300, or 600 mg/kg (Appendix D^50^).

#### Dose Selection Rationale for the Prenatal Developmental Toxicity Study in Rats

Due to overt maternal toxicity in dams administered 600 or 900 mg/kg and lack of significant maternal toxicity in those dosed with 300 mg/kg in the dose range-finding study, a high dose of 400 mg/kg was selected for the subsequent prenatal developmental toxicity study. The dose of 400 mg/kg was estimated to induce minimal maternal toxicity. A low dose of 50 mg/kg was included to extend the dose-response assessment. Thus, dose concentrations of 0, 50, 100, 200, and 400 mg/kg were selected for the prenatal developmental toxicity gavage study.

## Prenatal Developmental Toxicity Study in Rats

### Maternal Findings

#### Viability and Clinical Observations

No animals were removed from the study prior to scheduled necropsy (Table 6). No clinical observations of toxicity were observed in dams at any dose (Appendix D^50^).

Table 6 Maternal Disposition of Rats in the Prenatal Developmental Toxicity Gavage Study of 4-Methylcyclohexanemethanol

| 0 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg | 400 mg/kg
Time-mated Females | 25 | 25 | 25 | 25 | 25
Pregnant (on GD 21) | 23 | 21 | 22 | 19 | 21
Nonpregnant (on GD 21) | 2 | 4 | 3 | 6 | 4

GD = gestation day.

#### Body Weights and Feed Consumption

There was no effect on absolute body weight from GD 6 to 21. Overall maternal weight gain from GD 6 to 21 was 11% lower than that of vehicle controls in dams in administered 400 mg/kg (Figure 4 and Table 7). The overall decrease in 400 mg/kg dams reflects lower (41%) weight gains over the GD 6 to 9 interval, a rebound (25% increase) from GD 9 to 12, and lower (18%) weight gain over the GD 18 to 21 interval. The lower weight gain in late gestation in dams exposed to 400 mg/kg was associated with lower gravid uterine weight. Mean adjusted body weight at necropsy (minus gravid uterine weight) was unaffected with MCHM administration.

Figure 4

Maternal Growth Curves for Pregnant Rats Administered 4-Methylcyclohexanemethanol by Gavage in the Prenatal Developmental Toxicity Study

Information for statistical significance in maternal weights is provided in Table 7 and Appendix D.^50^

Table 7 Summary of Maternal Body Weight Gains of Rats in the Prenatal Developmental Toxicity Gavage Study of 4-Methylcyclohexanemethanol^a^

Gestation Day Interval | 0 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg | 400 mg/kg
6–21 | 131.4 ± 3.9** (23) | 141.5 ± 4.3 (21) | 130.1 ± 4.8 (22) | 129.6 ± 4.9 (19) | 116.5 ± 4.1* (21)
3–6 | 15.1 ± 2.2 (23) | 16.3 ± 2.1 (21) | 16.0 ± 2.3 (22) | 13.8 ± 1.2 (19) | 15.2 ± 1.9 (21)
6–9 | 12.3 ± 0.6** (23) | 12.9 ± 1.0 (21) | 10.8 ± 0.5 (22) | 10.2 ± 0.9 (19) | 7.2 ± 0.9** (21)
9–12 | 14.9 ± 0.6** (23) | 16.7 ± 0.7 (21) | 14.5 ± 0.6 (22) | 16.1 ± 1.0 (19) | 18.6 ± 0.7** (21)
12–15 | 18.8 ± 0.8 (23) | 19.3 ± 0.5 (21) | 18.4 ± 1.6 (22) | 18.5 ± 1.8 (19) | 18.2 ± 0.8 (21)
15–18 | 38.3 ± 1.4 (23) | 39.9 ± 3.0 (21) | 39.5 ± 1.9 (22) | 39.8 ± 2.1 (19) | 33.9 ± 1.6 (21)
18–21 | 47.1 ± 1.9** (23) | 52.8 ± 2.7 (21) | 47.0 ± 2.4 (22) | 44.9 ± 2.7 (19) | 38.6 ± 2.5* (21)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Williams or Dunnett test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Body weight gains for pregnant animals are given in grams. Data are displayed as mean ± standard error. Number of dams is given in parentheses.

Overall feed consumption (GD 6 to 21) was marginally increased 6–7% in the 200 and 400 mg/kg groups, respectively, compared to the vehicle control group (Table 8). Dams in the 400 mg/kg group displayed an increase in feed consumption (11%) from GD 9 to 12, which corresponds to the increased weight gain observed over the same interval.

Table 8 Summary of Maternal Feed Consumption of Rats in the Prenatal Developmental Toxicity Gavage Study of 4-Methylcyclohexanemethanol^a^

Gestation Day Interval | 0 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg | 400 mg/kg
6–21 | 20.7 ± 0.26** (23) | 21.2 ± 0.35 (21) | 21.2 ± 0.26 (22) | 21.9 ± 0.23** (19) | 22.1 ± 0.29** (21)
3–6 | 19.0 ± 0.34 (23) | 18.6 ± 0.37 (21) | 18.9 ± 0.24 (22) | 19.1 ± 0.33 (19) | 19.5 ± 0.40 (21)
6–9 | 19.0 ± 0.31 (23) | 18.9 ± 0.40 (21) | 19.0 ± 0.31 (22) | 19.8 ± 0.52 (19) | 17.9 ± 0.45 (21)
9–12 | 19.5 ± 0.35** (23) | 20.3 ± 0.37 (21) | 19.8 ± 0.31 (22) | 20.3 ± 0.30 (19) | 21.7 ± 0.37** (21)
12–15 | 20.2 ± 0.29** (23) | 20.3 ± 0.47 (21) | 20.4 ± 0.33 (22) | 21.1 ± 0.27 (19) | 22.2 ± 0.36** (21)
15–18 | 22.6 ± 0.40** (23) | 22.6 ± 0.59 (21) | 23.5 ± 0.47 (22) | 24.5 ± 0.39** (19) | 24.9 ± 0.52** (21)
18–21 | 22.4 ± 0.38* (23) | 23.7 ± 0.49 (21) | 23.3 ± 0.54 (22) | 23.7 ± 0.54 (19) | 23.8 ± 0.61 (21)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Shirley or Dunn test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Feed consumption for pregnant animals is given in grams/day. Data are displayed as mean ± standard error. Number of dams with feed consumption measured is given in parentheses.

### Maternal and Litter Observations

There were no maternal gross observations at any dose level (Appendix D^50^).

Because of the influence of pregnancy status on hematology and clinical chemistry, these data are presented only for pregnant animals (Appendix D^50^). Total protein concentrations were decreased (≤10%) in the 100, 200, and 400 mg/kg groups; this change was driven by a 10% decrease in the globulin concentrations in the same dose groups (Table 9). A mild decrease (6%) in calcium concentration was observed in the 400 mg/kg group. Calcium is mainly bound to albumin in circulation; therefore, decreases in albumin result in decreases in serum total calcium concentrations (versus serum ionized calcium). Although there was not a significant decrease in albumin concentration in the 400 mg/kg group, there was a significant downward trend with albumin 7% lower in the 400 mg/kg group compared to the vehicle control group.

Table 9 Selected Clinical Chemistry Findings in Rats in the Prenatal Developmental Toxicity Gavage Study of 4-Methylcyclohexanemethanol

| 0 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg | 400 mg/kg
Urea Nitrogen (mg/dL) | 17.9 ± 0.6** (23) | 17.7 ± 0.5 (21) | 17.5 ± 0.5 (22) | 18.7 ± 1.0 (19) | 20.8 ± 0.6** (21)
Glucose (mg/dL) | 181.2 ± 10.3** (23) | 153.9 ± 7.4 (21) | 176.0 ± 11.1 (22) | 150.6 ± 10.6* (19) | 141.3 ± 9.3** (21)
Calcium (mg/dL) | 12.2 ± 0.2* (22) | 11.7 ± 0.2 (21) | 11.8 ± 0.2 (22) | 11.7 ± 0.2 (19) | 11.4 ± 0.3* (20)
Total Protein (g/dL) | 5.17 ± 0.11** (23) | 4.93 ± 0.10 (21) | 4.84 ± 0.10* (22) | 4.91 ± 0.15* (19) | 4.74 ± 0.14** (21)
Albumin (g/dL) | 3.07 ± 0.09* (23) | 2.93 ± 0.07 (21) | 2.95 ± 0.10 (22) | 3.01 ± 0.12 (19) | 2.85 ± 0.13 (21)
Globulin (g/dL) | 2.10 ± 0.05** (23) | 2.01 ± 0.06 (21) | 1.89 ± 0.04** (22) | 1.90 ± 0.04** (19) | 1.89 ± 0.06** (21)
Triglycerides (mg/dL) | 145.5 ± 21.0** (23) | 114.8 ± 18.0 (21) | 94.6 ± 12.6 (22) | 108.4 ± 14.0 (19) | 194.6 ± 31.8* (21)
Alkaline Phosphatase (IU/L) | 138.4 ± 6.9 (23) | 142.0 ± 4.7 (21) | 131.7 ± 4.2 (22) | 134.9 ± 5.4 (19) | 157.0 ± 6.2* (21)

* Statistically significant (p < 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Shirley or Dunn test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p < 0.01.

^a^ Data are presented as mean ± standard error (number of animals); statistical tests were performed on unrounded data.

Glucose concentrations were decreased in the 200 mg/kg (17%) and 400 mg/kg (22%) groups, and triglyceride concentrations were increased (34%) in the 400 mg/kg group (Table 9). Although the mechanism is not known, these changes could indicate alterations in carbohydrate and lipid metabolism or might be due to differences in feed consumption relative to control animals. Blood urea nitrogen (BUN) was mildly increased (16%) in the 400 mg/kg group, whereas creatinine concentration was unchanged. A common cause of mildly increased BUN levels is decreased water intake (dehydration); although no other hematological or biochemical changes support this and water consumption was not assessed, a decrease in water intake was considered the most likely reason for this finding.

Alkaline phosphatase (ALP) activity was elevated (13%) in the 400 mg/kg group (Table 9). This hepatic enzyme could increase as a result of cholestasis; however, bilirubin was unchanged and the increase in ALP was minimal. The intestinal isoenzyme of ALP (along with the osseous isoenzyme) is the dominant form of serum ALP in rats and food intake is known to have a pronounced effect on serum ALP activity in rats.^51,52^ Thus, the minimal increases in ALP activity in the 400 mg/kg group could be due to increased feed consumption that was observed in this dose group during gestation, or alternatively, could represent normal biological variability.

The number of corpora lutea, implantation sites, and fetuses per litter were similar across the dose groups (Table 10). There was no effect on embryo-fetal viability with exposure to MCHM. The fetal sex ratios were similar across the dose groups.

Table 10 Summary of Uterine Content Data for Rats in the Prenatal Developmental Toxicity Gavage Study of 4-Methylcyclohexanemethanol

| 0 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg | 400 mg/kg
Pregnancy Summary
Mated females | 25 | 25 | 25 | 25 | 25
Pregnant females | 23 | 21 | 22 | 19 | 21
Pregnant females examined on GD 21^a^ | 23 | 21 | 22 | 19 | 21
Corpora lutea per female^b^ | 17.17 ± 0.43 (23) | 16.67 ± 0.85 (21) | 17.50 ± 0.70 (22) | 18.47 ± 1.11 (19) | 16.81 ± 0.63 (21)
Implantations per female^b^ | 13.83 ± 0.55 (23) | 14.33 ± 0.37 (21) | 13.23 ± 0.69 (22) | 13.74 ± 0.80 (19) | 13.05 ± 0.74 (21)
Percent postimplantation loss^b^ | 8.02 ± 2.47 (23) | 6.54 ± 3.13 (21) | 8.09 ± 4.50 (22) | 5.18 ± 1.96 (19) | 7.76 ± 2.51 (21)
Total resorptions per litter^b^ | 0.96 ± 0.20 (23) | 0.86 ± 0.36 (21) | 0.55 ± 0.14 (22) | 0.74 ± 0.27 (19) | 0.95 ± 0.30 (21)
Early resorptions per litter^b^ | 0.91 ± 0.21 (23) | 0.76 ± 0.28 (21) | 0.55 ± 0.14 (22) | 0.74 ± 0.27 (19) | 0.95 ± 0.30 (21)
Late resorptions per litter^b^ | 0.04 ± 0.04 (23) | 0.10 ± 0.10 (21) | 0.00 ± 0.00 (22) | 0.00 ± 0.00 (19) | 0.00 ± 0.00 (21)
Dead fetuses per litter^b^ | 0.00 ± 0.00 (23) | 0.00 ± 0.00 (21) | 0.00 ± 0.00 (22) | 0.00 ± 0.00 (19) | 0.00 ± 0.00 (21)
Number of early resorptions^c^ | 21 | 16 | 12 | 14 | 20
Number of late resorptions^c^ | 1 | 2 | 0 | 0 | 0
Number of dead fetuses | 0 | 0 | 0 | 0 | 0
Number of whole litter resorptions^c^ | 0 | 0 | 1 | 0 | 0
Live Fetuses^b^
Number of live fetuses | 296 | 283 | 279 | 247 | 254
Live fetuses per litter | 12.87 ± 0.64 (23) | 13.48 ± 0.58 (21) | 12.68 ± 0.71 (22) | 13.00 ± 0.81 (19) | 12.10 ± 0.79 (21)
Live male fetuses per litter | 6.26 ± 0.41 (23) | 7.14 ± 0.59 (21) | 7.05 ± 0.67 (22) | 6.26 ± 0.64 (19) | 6.05 ± 0.49 (21)
Live female fetuses per litter | 6.61 ± 0.42 (23) | 6.33 ± 0.51 (21) | 5.64 ± 0.51 (22) | 6.74 ± 0.58 (19) | 6.05 ± 0.56 (21)
Percent live male fetuses per litter | 49.89 | 51.95 | 54.80 | 49.29 | 51.02
Fetal Weight^d^ (g)
Fetal weight per litter | 5.14 ± 0.07 (23)** | 5.16 ± 0.08 (21) | 5.14 ± 0.07 (21) | 4.98 ± 0.09 (19) | 4.39 ± 0.09 (21)**
Male weight per litter | 5.28 ± 0.06 (23)** | 5.30 ± 0.08 (21) | 5.28 ± 0.07 (21) | 5.12 ± 0.09 (19) | 4.46 ± 0.09 (21)**
Female weight per litter | 4.99 ± 0.07 (22)** | 5.00 ± 0.08 (21) | 4.98 ± 0.07 (21) | 4.82 ± 0.09 (18) | 4.34 ± 0.12 (21)**
Gravid Uterine Weight^e^ (g)
Gravid uterine weight | 91.76 ± 4.05 (23)** | 96.88 ± 3.61 (21) | 90.41 ± 4.83 (22) | 88.57 ± 4.88 (19) | 75.58 ± 4.20 (21)**
Terminal body weight | 370.9 ± 5.7 (23)** | 381.5 ± 4.3 (21) | 370.1 ± 5.8 (22) | 368.8 ± 5.6 (19) | 356.9 ± 4.9 (21)
Adjusted body weight | 279.10 ± 2.70 (23) | 284.61 ± 2.55 (21) | 279.65 ± 2.61 (22) | 280.23 ± 2.47 (19) | 281.34 ± 3.23 (21)

Values are reported per litter as mean ± standard error (n) and do not include nonpregnant animals or those that did not survive to end of study.

** Statistically significant (p ≤ 0.01) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column).

GD = gestation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ No statistical analyses were performed on number of early resorptions, number of late resorptions, or number of whole litter resorptions.

^d^ Statistical analysis performed using a mixed-effects linear model with litter as a random effect (trend and pairwise).

^e^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests; adjusted body weight = total terminal body weight minus gravid uterine weight.

The mean numbers of live fetuses and early/late resorptions were similar across the dose groups. There was a significant decrease (15%) in fetal weights (males and females combined) in the 400 mg/kg group. There was no effect of MCHM exposure on fetal weights in the 50, 100, and 200 mg/kg groups.

### Fetal Findings

#### External

Low incidences of malformations (one to two fetuses) of absent anus and thread-like tail (occurred in the same fetus), bent tail, and omphalocele were noted. With the exception of bent tail in two fetuses from two litters in the 50 mg/kg group, these malformations were observed in fetuses in the 400 mg/kg group but were not considered to be a result of MCHM administration (Appendix D^50^).

#### Visceral

Visceral malformations and variations were limited to findings in the adrenal glands and kidneys at 400 mg/kg. These findings included misshapen and discolored adrenal glands (glands appeared grossly necrotic) and discolored kidneys (Table 11; Appendix D^50^). These three findings occurred together in one 50 mg/kg fetus and in each of three 400 mg/kg fetuses from three different litters (Table 11; Appendix D^50^). No other visceral findings were considered to be related to MCHM treatment.

Table 11 Summary of Selected Fetal Visceral Findings in Rats in the Prenatal Developmental Toxicity Gavage Study of 4-Methylcyclohexanemethanol

| 0 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg | 400 mg/kg
Total Number of Fetuses | 296 | 283 | 279 | 247 | 254
Number of Fetuses Examined | 296 | 283 | 279 | 247 | 254
Number of Litters Examined | 23 | 21 | 21 | 19 | 21
Abdominal Viscera
Adrenal, total, discolored – [V]^a^
Fetuses^b^ | 0 (0.0)* | 1 (0.4) | 0 (0.0) | 0 (0.0) | 3 (1.2)
Litters | 0 (0.00)* | 1 (4.76) | 0 (0.00) | 0 (0.00) | 3 (14.29)
Adrenal, total, misshapen – [M]^a^
Fetuses | 0 (0.0)* | 1 (0.4) | 0 (0.0) | 0 (0.0) | 3 (1.2)
Litters | 0 (0.00)* | 1 (4.76) | 0 (0.00) | 0 (0.00) | 3 (14.29)
Urinary Tract
Kidney, total, discolored – [V]^a^
Fetuses | 0 (0.0)* | 1 (0.4) | 0 (0.0) | 0 (0.0) | 3 (1.2)
Litters | 0 (0.00)* | 1 (4.76) | 0 (0.00) | 0 (0.00) | 3 (14.29)

Upper row denotes number of affected fetuses (%); lower row the number of affected litters (%).

* Statistically significant (p ≤ 0.05) trend according to the Cochran-Armitage (trend) test. None of the pairwise comparisons to the control group were statistically significant by the Fisher exact test. A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

[M] = malformation; [V] = variation.

^a^ Historical incidence for prenatal developmental toxicity gavage studies: fetuses: 0/1,326 (0%); litters 0/104 (0%).

^b^ Statistical analysis of fetuses performed by mixed-effects logistic regression models with litter-based adjustments found no statistically significant trend or pairwise comparison.

#### Head

No chemical-related increases were found in the incidences of variations or malformations of the skull in exposed fetuses (Appendix D^50^).

#### Skeletal

Several skeletal anomalies were observed in fetuses in the 400 mg/kg group. These variations and malformations occurred along the axial skeleton and included anomalies in the costal cartilage, sternebrae, and the presence of cervical and thoracolumbar supernumerary ribs (SNRs).

The incidence of the seventh, right costal cartilage not fusing to the sternum was increased in the 400 mg/kg group (Table 12; Appendix D^50^). Additionally, misaligned costal cartilage was observed in the fourth and fifth right ribs in one fetus and in multiple sites in two fetuses from different litters. When combined, there was a significant increase in the total litter incidences of misaligned costal cartilage in three fetuses from two litters in the 400 mg/kg group.

Table 12 Summary of Selected Fetal Skeletal Findings in Rats in the Prenatal Developmental Toxicity Gavage Study of 4-Methylcyclohexanemethanol

| 0 mg/kg | 50 mg/kg | 100 mg/kg | 200 mg/kg | | | 400 mg/kg
Total Number of Fetuses | 296 | 283 | 279 | 247 | | | 254
Number of Fetuses Examined | 296 | 283 | 279 | 247 | | | 254
Number of Litters Examined | 23 | 21 | 21 | 19 | | | 21
Ribs
Costal cartilage, 4th right, misaligned – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 0 (0.0) | | | 1 (0.4)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | | | 1 (4.76)
Costal cartilage, 5th right, misaligned – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 0 (0.0) | | | 1 (0.4)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | | | 1 (4.76)
Costal cartilage, multiple sites, misaligned – [V]
Fetuses | 0 (0.0)* | 0 (0.0) | 0 (0.0) | 0 (0.0) | | | 2 (0.8)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | | | 1 (4.76)
Costal cartilage, total, misaligned – [V]
Fetuses | 0 (0.0)** | 0 (0.0) | 0 (0.0) | 0 (0.0) | | | 3 (1.2)
Litters | 0 (0.00)* | 0 (0.00) | 0 (0.00) | 0 (0.00) | | | 2 (9.52)
Costal cartilage, 7th right, not fused to sternum – [M]^a^
Fetuses | 0 (0.0)** | 0 (0.0) | 0 (0.0) | 2 (0.8) | | | 4 (1.6)*
Litters | 0 (0.00)** | 0 (0.00) | 0 (0.00) | 1 (5.26) | | | 4 (19.05)*
Sternebrae
Sternebra, 2nd, unossified – [V]
Fetuses | 0 (0.0)** | 1 (0.4) | 0 (0.0) | 0 (0.0) | | | 4 (1.6)*
Litters | 0 (0.00)** | 1 (4.76) | 0 (0.00) | 0 (0.00) | | | 4 (19.05)*
Sternebra, 5th, unossified – [V]
Fetuses | 0 (0.0) | 1 (0.4) | 0 (0.0) | 0 (0.0) | | | 2 (0.8)
Litters | 0 (0.00) | 1 (4.76) | 0 (0.00) | 0 (0.00) | | | 2 (9.52)
Sternebra, 6th, unossified – [V]
Fetuses | 0 (0.0) | 1 (0.4) | 0 (0.0) | 0 (0.0) | | | 2 (0.8)
Litters | 0 (0.00) | 1 (4.76) | 0 (0.00) | 0 (0.00) | | | 2 (9.52)
Sternebra, multiple sites, unossified – [V]
Fetuses | 0 (0.0) | 0 (0.0) | 0 (0.0) | 0 (0.0) | | | 1 (0.4)
Litters | 0 (0.00) | 0 (0.00) | 0 (0.00) | 0 (0.00) | | | 1 (4.76)
Sternebra, total, unossified – [V]
Fetuses | 0 (0.0)** | 1 (0.4) | 0 (0.0) | 0 (0.0) | | | 6 (2.4)**
Litters | 0 (0.00)** | 1 (4.76) | 0 (0.00) | 0 (0.00) | | | 5 (23.81)*
Sternebra, 4th, misaligned – [V]
Fetuses | 0 (0.0)* | 0 (0.0) | 0 (0.0) | 0 (0.0) | | | 2 (0.8)
Litters | 0 (0.00)* | 0 (0.00) | 0 (0.00) | 0 (0.00) | | | 2 (9.52)
Sternebra, total, unossified or misaligned – [V]
Fetuses | 0 (0.0)** | 1 (0.4) | 0 (0.0) | 0 (0.0) | | | 7 (2.8)**
Litters | 0 (0.00)** | 1 (4.76) | 0 (0.00) | 0 (0.00) | | | 6 (28.57)**
Vertebrae
Thoracic centrum, total, incomplete ossification – [V]
Fetuses | 0 (0.0)* | 1 (0.4) | 0 (0.0) | | 0 (0.0) | | 3 (1.2)
Litters | 0 (0.00) | 1 (4.76) | 0 (0.00) | | 0 (0.00) | | 2 (9.52)
Thoracic centrum, total, incomplete ossification or unossified – [V]
Fetuses | 0 (0.0)** | 1 (0.4) | 0 (0.0) | | 0 (0.0) | | 4 (1.6)*
Litters | 0 (0.00)* | 1 (4.76) | 0 (0.00) | | 0 (0.00) | | 3 (14.29)
Supernumerary Rib
Cervical, total, short – [M]^b^
Fetuses | 0 (0.0)** | 0 (0.0) | 0 (0.0) | | 0 (0.0) | | 6 (2.4)**
Litters | 0 (0.00)** | 0 (0.00) | 0 (0.00) | | 0 (0.00) | | 3 (14.29)
Thoracolumbar, total, short – [V]
Fetuses | 76 (25.8)** | 56 (19.8) | 79 (28.3) | | 87 (35.2)* | | 77 (30.3)
Litters | 21 (91.30) | 19 (90.48) | 17 (80.95) | | 17 (89.47) | | 19 (90.48)
Thoracolumbar, total, full – [M]^c^
Fetuses | 2 (0.7)**^##^ | 1 (0.4) | 6 (2.2) | | 5 (2.0) | | 26 (10.3)**^##^
Litters | 2 (8.70)** | 1 (4.76) | 3 (14.29) | | 4 (21.05) | | 7 (33.33)*
Ribs, Sternebrae, Supernumerary Rib, or Vertebrae, Total
Incomplete Ossification or Unossified, Total – [V]
Fetuses | 0 (0.0)** | 2 (0.7) | 0 (0.0) | | 0 (0.0) | | 9 (3.6)**
Litters | 0 (0.00)** | 2 (9.52) | 0 (0.00) | | 0 (0.00) | | 7 (33.33)**
Malformation, total – [M]^d^
Fetuses | 3 (1.0)**^##^ | 3 (1.1) | 6 (2.2) | | 7 (2.8) | | 40 (15.8)**^##^
Litters | 3 (13.04)** | 3 (14.29) | 3 (14.29) | | 5 (26.32) | | 12 (57.14)**

Upper row denotes number of affected fetuses (%); lower row the number of affected litters (%).

* Statistically significant (p ≤ 0.05) trend according to the Cochran-Armitage (trend) or Fisher exact (pairwise) tests. A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^##^ Statistically significant (p ≤ 0.01) according to mixed-effects logistic regression with litter-based adjustments. A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

[M] = malformation; [V] = variation.

Historical incidence for gavage studies:

^a^ Fetuses: 2/1,324 (0.15%), range 0–0.41%; litters 2/104 (1.92%), range 0–5.56%.

^b^ Fetuses: 1/1,324 (0.08%), range 0–0.35%; litters 1/104 (0.96%), range 0–4.35%.

^c^ Fetuses: 14/1,324 (1.06%), range 0.34–3.35%; litters 13/104 (12.5%), range 4.76–31.6%.

^d^ Fetuses: 18/1,324 (1.36%), range 0.68–3.35%; litters 17/104 (16.3%), range 9.5–31.6%.

Increases in the number of unossified second, fifth, and sixth sternebrae were observed in the 400 mg/kg group; in one fetus, this occurred in multiple sites (Table 12; Appendix D^50^). In addition, there was an increase in the total incidences of unossified (first thoracic) or incompletely ossified (12th and 13th thoracic) vertebrae of the thoracic centrum due to the occurrence in four fetuses from three litters in the 400 mg/kg group. The sternal and vertebral ossification delays were consistent with the small size of the affected fetuses and with the reduced fetal weight at this exposure level.

There was an increase in the number of full thoracolumbar and short cervical SNRs. These malformations were significantly increased in the 400 mg/kg group (Table 12; Appendix D^50^).

Overall, the total incidences of skeletal malformations of the axial skeleton (ribs, sternebrae, SNRs, and vertebrae) were increased in an exposure-dependent manner. These malformations exceeded the historical control incidences (both fetal- and litter-based) observed in NTP prenatal developmental toxicity studies (Table 12; Appendix D^50^).