# Materials and Methods

## Overview of Prenatal Developmental Toxicity Study Designs

Prenatal developmental toxicity studies are conducted to ascertain if in utero exposure to a test agent results in embryo-fetal death, structural malformations/variations, growth retardation, or functional deficits not secondary to overt maternal toxicity. Overt maternal toxicity has been shown to affect normal embryo-fetal growth and development (e.g., excessively lower maternal body weight gains and lower fetal weights, increased maternal stress in mice, and cleft palate).^22-24^ The presence of maternal toxicity, however, should not negate a priori an apparent fetal response. Rather, given the maternal/embryo-fetal interrelationship, maternal responses should be considered when interpreting fetal findings. Pregnant animals should be administered the highest feasible dose levels of test agent (or the limit dose) to achieve maximal dam and fetal exposure and sufficiently challenge the test system to identify potential developmental hazards.^25^

The conduct of a dose range-finding study helps determine dose selection when the potential for test agent-induced maternal toxicity is unknown and can provide preliminary information on embryo-fetal outcomes (e.g., postimplantation loss, changes in fetal weight, external defects) and informs the design for a prenatal developmental toxicity study. In the prenatal developmental toxicity study, fetal examination is expanded to include examination of the fetal viscera, head (soft tissue and skeletal components), and the skeleton for osseous and cartilaginous defects. Abnormalities are categorized in one of two groups: (1) malformations that are permanent structural changes that could adversely affect survival, development, or function; and (2) variations that are a divergence beyond the usual range of structural constitution but might not adversely affect survival or health,^23^ consistent with the descriptions by Makris et al.^26^ The study design for the dose range-finding and prenatal developmental toxicity studies is presented in Figure 2.

Figure 2

Design of a Dose Range-finding and Prenatal Developmental Toxicity Study in Rats

^a^Animals are exposed once daily from gestation day (GD) 6 to GD 20 and necropsied on GD 21.

^b^All fetuses are examined externally (including inspection of the oral cavity). Fetuses in the prenatal developmental toxicity study also are examined for visceral and skeletal effects with approximately 50% of the heads examined for soft tissue alterations.

## Procurement and Characterization

### 4-Methylcyclohexanemethanol

4-Methylcyclohexanemethanol (MCHM) was obtained from TCI America (Portland, OR) in one lot (KDY3F). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO) for the study laboratory at Southern Research (Birmingham, AL) (Appendix A).

The chemical, a clear colorless liquid, was identified as MCHM using Fourier transform infrared (FTIR) spectrometry, proton and carbon-13 nuclear magnetic resonance spectroscopy, and gas chromatography (GC) with mass spectrometry detection. In addition, boiling point, density, and octanol:water partition coefficient were determined. Purity of the test article was determined by elemental analyses and GC with flame ionization detection (FID) and two columns with differing polarities.

Karl Fischer titration indicated 0.209% water. Elemental analyses for carbon, hydrogen, and nitrogen were consistent with the theoretical values for MCHM. GC/FID analysis by one system detected two major peaks with a combined area of 99.97% of the total peak area and no impurities with areas ≥0.05% of the total peak area. The relative areas of the two major peaks indicated that MCHM consisted of 67.99% cis- and 31.98% trans-isomers. GC/FID by a second system detected two major peaks with a combined relative area of 99.83% (with relative areas of 67.80% [cis-] and 32.03% [trans-] isomers), and two minor impurities totaling 0.13% of the total peak area. The overall purity of lot KDY3F was determined to be greater than or equal to 99.8%.

Stability studies of the bulk chemical were conducted using GC/FID. These studies indicated that MCHM was stable as a bulk chemical for 2 weeks when stored in amber glass vials under an inert headspace, sealed with aluminum caps with Teflon^®^-lined septa at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature under an inert headspace in amber glass bottles. Reanalyses of the bulk chemical were performed using FTIR and GC/FID, and no degradation of the bulk chemical was detected.

### Corn Oil

Corn oil was obtained from Spectrum Laboratory Products, Inc. (Gardena, CA) in two lots (1CK0678 and 2DG0376) that were used as the vehicle in the dose range-finding and prenatal developmental toxicity studies, respectively. A solubility study of MCHM was performed by the analytical chemistry laboratory; after 17 days under refrigerated conditions, the test article remained soluble in corn oil at up to 600 mg/mL with no remixing required. Both lots contained peroxide levels that were less than the rejection level of 3 milliequivalents (meQ)/kg corn oil.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared once for the dose range-finding study and once for the prenatal developmental toxicity study by mixing the appropriate amount of MCHM with corn oil. Stability studies of 0.20 and 2.0 mg/mL formulations were performed by the analytical chemistry laboratory using GC/FID. For the 0.20 mg/mL formulation, stability was confirmed for at least 42 days during which the formulation was stored under ambient or refrigerated conditions and protected from light, and for 3 hours under simulated animal room conditions. In addition, for the 2.0 mg/mL formulation, stability was confirmed for at least 44 days during which it was stored under ambient or refrigerated conditions and protected from light.

Analyses of the dose formulations of MCHM were conducted by the analytical chemistry laboratory using GC/FID. During the dose range-finding study, the dose formulations were analyzed once; all four dose formulations were within 10% of the target concentrations (Table A-3). Animal room samples of these dose formulations were also analyzed; all four animal room samples were within 10% of the target concentrations. During the prenatal developmental toxicity study, the dose formulations were analyzed once; animal room samples of these dose formulations were analyzed twice (Table A-4). All four dose formulations analyzed were within 10% of the target concentrations and all eight animal room samples were within 10% of the target concentrations.

## Animal Source

Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats for use in the dose range-finding and prenatal developmental toxicity studies were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN). Sexually mature (12 to 13 weeks old) females were time-mated overnight at the vendor and were received on gestation day (GD) 1 or 2 for both the dose range-finding and prenatal developmental toxicity studies. GD 0 was defined as the day positive evidence of mating was observed.

## Animal Health Surveillance

Disease screening was not conducted at the laboratory in the rats; however, rats were obtained from a commercial colony free of the following rat pathogens: Sendai virus, pneumonia virus of mice, sialodacryoadenitis virus, Kilham rat virus, Toolan’s H1 virus, rat minute virus, reovirus, rat theilovirus, lymphocytic choriomeningitis virus, hantavirus, mouse adenovirus, rat parvovirus, Mycoplasma pulmonis, and Pneumocystis carinii.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Southern Research Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Experimental Design

In the dose range-finding and prenatal developmental toxicity studies, time-mated rats were housed individually, provided NIH-07 feed and water ad libitum, and observed at least twice daily for viability (morning and afternoon, with at least 6 hours between observations). Clinical observations were recorded at least once from GD 3 through GD 5 and then daily during dosing (GD 6 through GD 20) until removal (1 to 3 hours after dosing). Dams were weighed daily from GD 3 through GD 21 (dose range-finding study) or on arrival, on GD 3, and daily from GD 6 through GD 21 (prenatal developmental toxicity study). Feed consumption was recorded for GD 3 to 6, GD 6 to 9, GD 9 to 12, GD 12 to 15, GD 15 to 18, and GD 18 to 21. Details of the study design—including animal source and identification, diet, water, husbandry, environmental conditions, euthanasia, necropsy, and fetal evaluations—are summarized in Table 1. Information on feed composition and contaminants is provided in Appendix B.

Table 1 Experimental Design and Materials and Methods in the Dose Range-finding and Prenatal Developmental Toxicity Gavage Studies of 4-Methylcyclohexanemethanol

Dose Range-finding Study | Prenatal Developmental Toxicity Study
Study Laboratory
Southern Research (Birmingham, AL) | Southern Research (Birmingham, AL)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN)
Day of Arrival
GD 1 or 2 (August 20, 2014) | GD 1 or 2 (November 12, 14, or 19, 2014)
Average Age on Arrival
13 weeks | 12 to 13 weeks
Weight Range at Randomization
206.7 to 266.2 g on GD 3 | 218.6 to 271.9 g on GD 3
Calendar Day of First Dose (GD 6) and Last Dose (GD 20)
GD 6 (August 24 or 25, 2014) and GD 20 (September 7 or 8, 2014); staggered start | GD 6 (November 16, 17, 18, 19, or 23, 2014) and GD 20 (November 30 or December 1, 2, 3, or 7, 2014); staggered start
Duration of Dosing
GD 6 to 20, once daily | GD 6 to 20, once daily
Size of Study Groups
10 time-mated females | 25 time-mated females
Method of Randomization and Identification
Time-mated animals were uniquely identified on day of receipt by ink tail marking and assigned to exposure group by body weight stratified randomization of GD 3 body weights using Instem Provantis^®^ (version 8) electronic data collection system. Each animal was assigned a unique animal number in Provantis. This number was linked to the respective marking and all data collected during the study was associated with the Provantis animal number. | Same as dose range-finding study
Animals per Cage
1 | 1
Diet
Irradiated NIH-07 pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly | Same as dose range-finding study
Water
Tap water (Birmingham, AL, municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as dose range-finding study
Cages
Solid bottom polycarbonate (Lab Products, Seaford, DE), changed weekly | Same as dose range-finding study
Bedding
Certified irradiated Sani-Chips^®^ hardwood cage bedding (P.J. Murphy Forest Products Corporation, Montville, NJ), changed weekly | Same as dose range-finding study
Cage Filters
Reemay^®^ spunbonded polyester (Andico, Birmingham, AL), changed every 2 weeks | Same as dose range-finding study
Racks
Stainless steel (Lab Products, Inc.), changed every 2 weeks | Same as dose range-finding study
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 17/hour | Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 19/hour
Doses
0, 150, 300, 600, or 900 mg/kg in corn oil (dosing volume 2 mL/kg) | 0, 50, 100, 200, or 400 mg/kg in corn oil (dosing volume 2 mL/kg)
Type and Frequency of Observation of Dams
Observed for viability (cageside) twice daily from GD 3 through GD 20. Clinical observations (out of cage) were recorded at least once from GD 3 through GD 5 and then daily beginning GD 6 at 1 to 3 hours post dose, and at the end of the study. Animals were weighed daily beginning on GD 3. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21. | Observed for viability (cageside) at least twice daily from GD 3 through GD 20. Clinical observations (out of cage) were recorded at least once from GD 3 through GD 5 and then daily beginning GD 6 at 1 to 3 hours post dose, and at the end of the study. Animals were weighed on the day of arrival, on GD 3, and daily beginning on GD 6. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21.
Primary Method of Euthanasia
100% CO_2_ (dams) or intraperitoneal injection of solution containing sodium pentobarbital followed by bilateral pneumothorax and/or decapitation (fetuses GD ≥15) | Same as dose range-finding study
Necropsy and Postmortem Evaluation of Females
On GD 21, terminal body weights, kidney and liver weights, and gravid uterine weights were recorded, and the uterine contents examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live or dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained with a 10% aqueous solution of ammonium sulfide to visualize potential evidence of implantation sites. For early removals, gross necropsy including an examination of the thoracic and abdominal viscera was performed. The uterus of each dam was examined to determine pregnancy status, or, if no evidence of pregnancy, stained with a 10% aqueous solution of ammonium sulfide to visualize possible early implantation sites. | On GD 21, terminal body weights and gravid uterine weights were recorded, and the uterine contents examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live or dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained with a 10% aqueous solution of ammonium sulfide to visualize potential evidence of implantation sites. There were no early removals.
Clinical Pathology
None | Blood was collected from surviving dams by cardiac puncture at the time of euthanasia for hematology and clinical chemistry analyses. Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, platelet, and nucleated erythrocyte counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical Chemistry: urea nitrogen, creatinine, glucose, calcium, phosphorus, total protein, albumin, globulin, albumin/globulin ratio, total bilirubin, direct bilirubin, cholesterol, triglycerides, alanine aminotransferase, alkaline phosphatase, aspartate aminotransferase, and creatine kinase
Fetal Evaluation
Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities that included inspection of the oral cavity for cleft palate. | Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities that included inspection of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were euthanized and then examined for visceral morphological abnormalities by fresh dissection. The sex of each fetus was confirmed by internal examination. The heads from approximately one-half of the fetuses in each litter were fixed, sectioned, and examined. All fetuses were eviscerated, fixed, stained, and examined for skeletal developmental variations, malformations, or other morphological findings.

GD = gestation day.

On GD 21, dams were weighed, euthanized with CO_2_, and examined for gross lesions of the thoracic and abdominal cavities. The gravid uterus and ovaries were excised and weighed (organs for prenatal developmental toxicity study only), and any placental findings were recorded. The numbers of uterine implantation sites and corpora lutea visible on the surface of each ovary were recorded. Uterine contents were examined for pregnancy status, and the numbers and locations of all live and dead fetuses (a live fetus is defined as one that responds to stimuli; a dead fetus is defined as a term fetus that does not respond to stimuli and is not markedly autolyzed) and resorptions were recorded.

Resorptions were classified as early or late. Early resorptions included a conceptus characterized by a grossly necrotic mass that had no recognizable fetal form and presence of nidation sites (“pregnant by stain”). Late resorptions were characterized by grossly necrotic but recognizable fetal form with placental remnants visible.^27,28^ Postimplantation loss was calculated as the number of dead and resorbed conceptuses divided by the total number of implantations (multiplied by 100). For each uterus with no macroscopic evidence of implantation, the uterus was stained with 10% (v/v) ammonium sulfide to visualize any possible implantation sites.^29^ In the dose range-finding study, the left and right kidney and liver were also weighed.

Adult females that were euthanized moribund, delivered early, or found dead received a gross necropsy that included an examination of the thoracic and abdominal viscera for evidence of dosing trauma or toxicity. The uterus of each female was examined and stained, if necessary, to determine pregnancy status. Dams were not retained for further examination.

### Dose Range-finding Study

Time-mated rats were individually identified by tail marking and randomized by GD 3 body weight stratification into five treatment groups using the Instem™ Provantis^®^ (version 8) electronic data collection system.

Groups of 10 time-mated female rats were administered 0 (vehicle control), 150, 300, 600, or 900 mg MCHM/kg body weight per day (mg/kg/day) (based on the most recent body weight) in corn oil by gavage from GD 6 to GD 20. The top dose of 900 mg MCHM/kg per day was selected consistent with the limited data available for MCHM, which includes a 5-day oral gavage study of doses up to 800 mg/kg/day (n = 2 animals/sex/dose) that was used to select doses for a subsequent 28-day subchronic study.^11^ Vehicle control animals received the corn oil vehicle alone; the dosing volume was 2 mL/kg body weight.

On GD 21, fetuses were removed from the uterus, individually weighed (live fetuses only), and examined externally for morphological alterations, including inspection of the oral cavity for cleft palate. Live fetuses were euthanized by intraperitoneal injection of a commercially available solution of sodium pentobarbital followed by bilateral pneumothorax and/or decapitation. External findings were recorded as developmental variations or malformations. Fetuses were not retained following completion of the external examination.

### Prenatal Developmental Toxicity Study

On receipt (GD 1 or 2), time-mated rats were individually identified by tail marking and were randomized by GD 3 body weight stratification into five treatment groups using the Instem™ Provantis^®^ (version 8) electronic data collection system.

Groups of 25 time-mated female rats were administered 0 (vehicle control), 50, 100, 200, or 400 mg MCHM/kg per day (based on the most recent body weight) in corn oil by gavage from GD 6 to GD 20. Vehicle control animals received corn oil vehicle alone; the dosing volume was 2 mL/kg.

On GD 21, fetuses were removed from the uterus, and live fetuses individually weighed. The uteri of animals that did not appear pregnant were examined for nidations (implantation sites) by staining with 0.5% ammonium sulfide.^29,30^ All fetuses were examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were subsequently euthanized by intraperitoneal injection of sodium pentobarbital. Fetal sex was confirmed by inspection of gonads in situ. All fetuses were examined for soft tissue alterations under a stereomicroscope.^31,32^ The heads were removed from approximately half of the fetuses in each litter and fixed in Bouin’s solution and subsequently examined by free-hand sectioning.^33^ This technique precludes skeletal evaluations of the skull; therefore, remaining heads and all fetuses were eviscerated, fixed in ethanol, macerated in potassium hydroxide, stained with alcian blue and alizarin red, and examined for subsequent cartilage and osseous alterations.^30,34^ External, visceral, and skeletal fetal alterations were recorded as developmental variations or malformations.

Additionally, blood was collected by cardiac puncture from the dams at the time of euthanasia for clinical pathology. Blood was collected into tubes containing potassium EDTA as the anticoagulant for hematology or no anticoagulant for clinical chemistry samples. The contents of the tubes containing anticoagulant were mixed by gentle inversion and maintained at room temperature. Samples obtained for hematology and clinical chemistry were analyzed on the day the samples were collected. Hematology analyses were performed on an Advia 120 analyzer (Siemens Healthcare Diagnostics, Tarrytown, NJ), except manual hematocrit determinations were performed using a microcentrifuge. Platelet, leukocyte, and erythrocyte morphology and nucleated erythrocytes were assessed using smears stained with a Romanowsky-type aqueous stain in a HemaTek Slide Stainer (Siemens Healthcare Diagnostics, Tarrytown, NJ). Serum samples for clinical chemistry analyses were centrifuged, the serum harvested, and analyses performed on a Cobas c501 analyzer (Roche Diagnostic Corp., Indianapolis, IN). The parameters measured are listed in Table 1.

## Statistical Methods

In both the dose range-finding study and the main study, statistical analyses were performed on data from pregnant females that survived until the end of the study and were examined on GD 21 and from live fetuses. Statistical analyses were performed using SAS 9.3 (SAS Institute, Cary, NC).

### Descriptive Statistics

Maternal Parameters: Maternal body weights were measured daily starting at GD 3 and reported as means. Terminal maternal body weights at GD 21 were adjusted for gravid uterine weight by subtracting the gravid uterine weight from the dam’s body weight. Body weight gains were calculated over each 3-day interval and from GD 6 to GD 21. Daily feed consumption was averaged over each 3-day interval and from GD 6 to GD 21. These continuous variables, in addition to gravid uterine weights, other organ weights, hematology, and clinical chemistry were summarized with means and standard errors.

Placental and Fetal Parameters: Data on uterine contents are reported as means and standard errors of counts per dam/litter (corpora lutea, implants, resorptions, dead fetuses) and as total numbers of occurrences (resorptions, dead fetuses). Data from females that were not pregnant or that did not survive to the end of the study were not included. Postimplantation loss is calculated as a percentage of the number of implants per dam. Fetal findings are reported as means and standard errors of counts per litter (numbers of live fetuses, male fetuses, female fetuses), means and standard errors of litter means (fetal weight, male fetal weight, female fetal weight), and total numbers of occurrences (total number of live fetuses). In addition, several calculated variables are reported, including the percentage of live male and female fetuses per litter.

Incidences of morphological findings from the gross, external, visceral, skeletal, and head examinations of pathology of placentae and fetuses are presented as number and percentage of affected fetuses and as number and percentage of affected litters.

### Analysis of Maternal Parameters and Uterine Contents

Maternal organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^35^ and Williams.^36,37^ Non-normally distributed variables, such as food consumption, hematology, clinical chemistry, and uterine content endpoints, were analyzed using the nonparametric multiple comparison methods of Shirley^38^ (as modified by Williams^39^) and Dunn.^40^ For normally distributed and non-normally distributed variables, the Jonckheere test^41^ was used to assess the significance of dose-related trends at p < 0.01 to determine whether a trend-sensitive test (the Williams or Shirley test) was more appropriate than a test that does not assume a monotonic dose-related trend (the Dunnett or Dunn test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^42^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

Fetal body weights were analyzed using mixed-effects linear models, with litter as a random effect to account for potential within-litter correlations. To test for a linear trend, dose was entered into the model as its numeric value and its significance was evaluated. For pairwise comparisons with the control group, a second mixed-effects model with dose entered into the model as a categorical variable was estimated, followed by the Dunnett^35^ and Hsu^43^ multiple comparisons tests.

### Analysis of Incidences of Gross Pathology and Morphology Findings

Incidences of gross findings, malformations, and variations in the fetuses were summarized and analyzed as number of litters affected and as number of fetuses affected. Incidences of gross findings, malformations, and numbers of litters affected were analyzed using the Cochran-Armitage trend test^44^ and the Fisher exact test.^45^ Numbers of fetuses affected were analyzed using mixed-effects logistic regression in which the litter was a random effect to account for potential litter effects.^46-48^ For each fetal finding, an initial mixed-effects logistic regression model used the numerical value of the dose to assess the significance of an exposure-related trend; a subsequent logistic regression model incorporated dose as a categorical variable to compare each dose group with the control group. To conduct the mixed-effects logistic regression analyses, at least one finding was required per dose group and the correlation matrix describing the relationship between litters was required to be “positive definite.” If the mixed-effects logistic regression failed to converge or did not meet the specified criteria, two separate analyses were used to bracket the true p value. The Cochran-Armitage trend test and the Fisher exact test were used with the litter as the experimental unit to calculate the upper limit for the true p value and with the fetus as the experimental unit to calculate the lower limit for the true p value.

### Historical Control Data

The concurrent control group is the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP developmental and reproductive toxicity studies. Historical control data are often helpful, however, in interpreting potential exposure-related effects, particularly for uncommon fetal findings that occur at a very low incidence. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Factors that might affect the background incidences of fetal findings at a variety of anatomical sites are diet, sex, strain/stock, route of exposure, study type, and/or laboratory that conducted the study. The NTP historical control database for teratology studies contains all fetal evaluations (e.g., teratology studies or modified one-generation studies) for each laboratory. In general, the historical control database for a given study includes studies using the same route of administration and study design. Historical control data for rats in this NTP Developmental and Reproductive Toxicity Technical Report are from gavage studies conducted at Southern Research. The concurrent controls are included in the historical control data set. NTP historical controls are available online at https://ntp.niehs.nih.gov/go/historical_controls.

## Quality Assurance Methods

The dose range-finding and prenatal developmental toxicity studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58).^49^ Records from these studies were submitted to the NTP Archives. The prenatal developmental toxicity study was audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the final study data tables for the dose range-finding and prenatal developmental toxicity studies and a draft of this NTP Developmental and Reproductive Toxicity Technical Report. Audit procedures and findings are presented in the reports and are on file at the NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.