# Introduction

Figure 1

4-Methylcyclohexanemethanol (CASRN: 34885-03-5; Chemical Formula: C_8_H_16_O; Molecular Weight: 128.21)

Synonyms: Cyclohexanemethanol, 4-methyl-; MCHM.

## Chemical and Physical Properties

The organic compound 4-methylcyclohexanemethanol (MCHM) has a molecular weight of 128.21 g/mol and a density of 0.9074 g/cm^3^. MCHM has estimated boiling and melting points of 203.7°C and −12.0°C, respectively, and a vapor pressure of 0.0588 mm Hg at 25°C. It has a low estimated water solubility of 2.024 × 10^3^ mg/L (at 25°C) and an estimated log K_OW_ of 2.55. MCHM is a clear, colorless oil and has been reported to have an alcohol or licorice-like odor.^1-3^

## Production, Use, and Human Exposure

The production volume of MCHM is not available, but it is typically sold as a crude mixture for use as a frothing agent to remove impurities during the processing of coal. The crude mixture contains 68–89% MCHM with other components including 4-(methoxymethyl)cyclohexanemethanol (4–22%), water (4–10%), methyl 4-methylcyclohexanecarboxylate (5%), dimethyl 1,4-cyclohexanedicarboxylate (1%), methanol (1%), and 1,4-cyclohexanedimethanol (1–2%).^3^ Exposure to MCHM can occur via dermal or inhalation routes during the handling or use of the chemical. Of the cis- and trans-isomers, the trans-MCHM is thought to be the dominant source of the licorice odor with an air odor threshold concentration of 0.060 ppb/v.^4,5^

On January 9, 2014, approximately 10,000 gallons of a mixture of chemicals containing predominantly MCHM leaked into the Elk River upstream of the intake for West Virginia American Water Company’s Elk River plant, a municipal water source serving approximately 300,000 people in Charleston, West Virginia.^6^ A number of chemicals were identified in the spill, including crude MCHM (estimated at 88.5%), propylene glycol ether, and dipropylene glycol phenyl ether.^7^ Of the crude MCHM in the mixture, MCHM alone was estimated to be 75% of the entire 10,000-gallon spill.^8^ The spill temporarily contaminated 15% of the state’s tap water, and prior to flushing, concentrations of MCHM in tap water ranged from less than 10 to 420 ppb; levels of the other components of crude MCHM were not measured.^9^ Concentrations of MCHM were also measured at the intake (up to 3.35 ppm) and posttreatment (up to 2.4 ppm).^6^ Exposure to 2.4 ppm is approximately equivalent to 0.07 mg/kg body weight per day for an adult (70 kg) consuming 2 L of water a day, 0.10 mg/kg/day for a pregnant woman (58 kg) consuming 2.5 L of water a day, and 0.24 mg/kg/day for a child (10 kg) consuming 1 L of water a day. Levels of the other components of crude MCHM were not measured.

## Regulatory Status

Workplace exposure limits for MCHM are currently unavailable. Immediately following the Elk River spill, the Centers for Disease Control and Prevention (CDC) and the Agency for Toxic Substances and Disease Registry (ATSDR) established a short-term drinking water limit of 1 ppm that was based on the approximate weight (10 kg) and drinking water intake (1 L) of a child.^8^ Evaluation of the same data using differing adjustment factors resulted in a calculated health advisory level of 120 ppb.^10^

## Absorption, Distribution, Metabolism, and Excretion

The literature contains no studies on the absorption, distribution, metabolism, or excretion of MCHM in experimental animals or humans.

## Developmental and Reproductive Toxicity

### Experimental Animals

The literature contains no guideline developmental or reproductive toxicity studies of MCHM. In a 28-day repeat oral exposure study, no effects were observed on the histology of the testis or ovaries.^11^ NTP conducted guideline prenatal developmental toxicity studies in alternative models, including the nematode (Caenorhabditis elegans) and zebrafish (Danio rerio). MCHM did not display signs of toxicity in growth, development, feeding, or reproduction in the nematode assay.^12^ In zebrafish, no effects on embryonic and early larval development toxicity were observed following exposure to MCHM at concentrations of up to 100 μM (12.8 ppm) for 120 hours.^13^ Some indications of developmental neurotoxicity were identified in the zebrafish model with reduced embryo reaction to light pulses at concentrations of 35 to 100 μM MCHM.^14^

### Humans

The literature contains no studies on the developmental or reproductive toxicity of MCHM in humans.

## General Toxicity

### Experimental Animals

The acute dermal toxicity of MCHM was evaluated in male and female rats [Crl:CD(SD)BR] administered a single topical dose (0, 2, 6, or 20 mL/kg).^15^ A dermal LD_50_ value of 3.6 mL/kg was determined for both males and females.

Oral LD_50_ values for MCHM were determined from an acute oral toxicity study in rats [Crl:CD(SD)BR] administered a single dose (0, 625, 1,250, or 2,500 mg/kg) by oral gavage.^15^ LD_50_ values of 1,768 and 884 mg/kg were calculated for male and female rats, respectively.

Administration of 0.5 mL MCHM in a guinea pig dermal irritation study (Crl:[HA]BR Hartley; n = 5) resulted in strong irritation 24 hours after an occluded single dose.^15^ In the same guinea pig species, a repeated skin test (9 applications over 11 days) of 0.5 mL MCHM found an increased irritant response with moderate edema, moderate necrosis, and moderate to strong eschars.^15^ MCHM was not found to be a skin sensitizer in the guinea pig (n = 10) after application of 0.05 mL to the footpad and was determined to be a moderate eye irritant in New Zealand white rabbits after a single application of 0.1 mL.^15^

In skin irritation and sensitization studies by NTP, mild skin irritation was induced in BALB/c mice after 3 days of application of 0%, 2%, 20%, or 50% MCHM solution in 4:1 acetone:olive oil (vehicle); hypersensitivity was not induced by the same concentrations.^16,17^

In a preliminary study to determine doses for a 28-day toxicity study, two male and two female rats were orally administered 0, 200, 400, or 800 mg MCHM/kg body weight per day (mg/kg/day) via oral gavage for 5 days. Clinical signs of ataxia and decreased activity were observed in both sexes at 800 mg/kg, and one female rat was euthanized.^11^

Male and female rats exposed to MCHM (0, 25, 100, or 400 mg/kg/day) by oral gavage, 5 days per week for 4 weeks exhibited increased liver weights, kidney tubular degeneration, and inflammation at 400 mg/kg.^11^ A no-observed-effect level (NOEL) was set at 100 mg/kg. The results of that study were used by ATSDR to establish the short-term drinking water limit of 1 ppm for MCHM.

MCHM was found to activate a low number of genes associated with gene expression pathways within the rat liver after 5 days of exposure.^18^ Benchmark dose values of these pathways ranged from 107 to 495 mg/kg/day. In the same study, no significant changes were observed in kidney gene expression. Other effects observed in the 5-day toxicogenomic study included decreases in thymus weight at 300 and 500 mg/kg/day and an increase in triglycerides and a slight increase in liver weight at 500 mg/kg/day.

### Humans

No direct studies of MCHM exposure on human health have been conducted. An indirect measurement of potential human health effects following the Elk River spill was conducted via a survey of 498 households and found that 159 households reported an illness related to the spill.^19^ These health effects consisted of rash or skin irritation, nausea or vomiting, diarrhea or abdominal cramps, headache or dizziness, or eye irritation.

## Genetic Toxicity

MCHM was evaluated for genetic toxicity by NTP. It was negative in a micronucleus assay after 5 days of exposure in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats.^20^ In addition, MCHM was negative up to 1,000 μg/plate in two Salmonella typhimurium strains and one Escherichia coli strain.^21^

## Study Rationale

The CDC and the ATSDR nominated MCHM and other chemicals associated with the Elk River spill to NTP for toxicity evaluation. In response, NTP conducted a number of studies of relatively short duration to provide information relevant to the potential exposures of the Charleston, West Virginia, residents. Because of the potential exposure to pregnant women and the developing fetus during gestation and concern for potential future exposures, NTP conducted prenatal developmental toxicity studies in rats to assess potential MCHM toxicity.