# Appendix D Supplemental Files

The following supplemental files are available at https://doi.org/10.22427/NTP-DATA-DART-02.

## D.1 Prenatal Developmental Toxicity Dose Range-finding Study – Rats

Readme File – Prenatal Dose Range Finding Study

Materials and Methods – Prenatal Developmental Toxicity Dose Range Finding Study

Chemical Methods – WV Chemical Spill NTP Studies

Animal Removal Summary

Clinical Observations Summary

Fetal Defect Summary

Fetal Defects

Gross Pathology Summary

Growth Curve

Mean Body Weight Gain

Mean Body Weights and Survival

Mean Feed Consumption

Organ Weights Summary

Placental Findings

Uterine Content Summary

Individual Animal Body Weights

Individual Animal Clinical Observations

Individual Animal Dam Findings

Individual Animal Food Consumption

Individual Animal Gross Pathology

Individual Animal Implant Findings

Individual Animal Organ Weights

Individual Animal Removal Reasons

## D.2 Prenatal Developmental Toxicity Study – Rats

Readme File – Prenatal Main Study

Materials and Methods – Prenatal Developmental Toxicity Study

Chemical Methods – WV Chemical Spill NTP Studies

Animal Removal Summary

Clinical Chemistry Summary

Clinical Observations Summary

Dam Pup Cross Reference

Fetal Defect Cross Reference Summary

Fetal Defect Summary

Fetal Defects

Gross Pathology Summary

Growth Curve

Hematology Summary

Mean Body Weight Gain

Mean Body Weights and Survival

Mean Feed Consumption

Placental Findings

Uterine Content Summary

Individual Animal Body Weights

Individual Animal Clinical Chemistry

Individual Animal Clinical Observations

Individual Animal Dam Findings

Individual Animal Food Consumption

Individual Animal Gross Pathology

Individual Animal Hematology

Individual Animal Implant Findings

Individual Animal Removal Reasons